# Discussion

Using systematic review methodologies, this scoping review of peer-reviewed, published scientific literature identified a sizable body of evidence comprising 458 studies that provide information about the association between exposure to paraquat and potential development of Parkinson’s disease (Figure 1). Interactive evidence maps were developed to allow readers to sort and explore the published scientific literature by study type, exposure scenarios, and measured endpoints. These maps include eight Tableau figures with qualitative summaries of the characteristics of each line of evidence, as well as three HAWC figures with quantitative summaries of the epidemiological evidence. All or part of this evidence base could be followed and updated over time to monitor the field and scientific advances.

A total of 24 human studies investigating the association between paraquat exposure and primary effects of Parkinson’s disease were identified, with the majority being case-control studies (Figure F-1). The largest studies focused on occupational exposures including the Agricultural Health Study (AHS), a large prospective cohort of agricultural workers in the United States, and the nested case-control studies in the Farming and Movement Evaluation (FAME) cohort, which reported significant associations between paraquat exposures and prevalence of Parkinson’s disease (Furlong et al. 2015; Goldman et al. 2012; Kamel et al. 2014; Kamel et al. 2007; Tanner et al. 2011). In these studies, paraquat exposures and co-exposures to other pesticides were captured by questionnaires. Although no formal study quality assessment was performed, some characteristics of the overall evidence base were noted. For example, most epidemiological studies reported few cases of Parkinson’s disease and were conducted in locations with higher environmental exposures (e.g., residences or workplaces near agricultural fields); few studies with exposures representative of the general population were identified.

Whereas human studies evaluated self-reported or clinician-confirmed cases of Parkinson’s disease or symptoms of parkinsonism, evidence in experimental animals and in vitro model systems comprised models of parkinsonism symptoms or known/suspected mechanisms leading to Parkinson’s disease in humans. To develop the inclusion criteria for these studies, the National Toxicology Program (NTP) worked closely with the U.S. Environmental Protection Agency (EPA) Office of Pesticide Programs (OPP) to identify primary outcomes that were most directly related to human Parkinson’s disease, such as loss of dopaminergic neurons and neuromuscular deficits, as well as secondary outcomes that were more mechanistic in nature, such as decreases in dopamine and other biochemical changes associated with Parkinson’s disease, and more general responses including changes in gene expression and oxidative stress levels.

A total of 143 experimental animal studies reported primary endpoints with 113 studies reporting effects observed in mammals (Figure 2) and 30 studies in nonmammalian models (Figure 6). The experimental designs across these studies differed with a variety of dosing regimens and measured health endpoints with some specifically designed to model some component of Parkinson’s disease and others that were not. The most commonly reported outcome categories were neuromuscular effects, including effects on locomotor activity, as well as dopaminergic neuron degeneration. In most of these studies, paraquat was administered via injection, whereas humans are mainly exposed via dermal, inhalation, or oral routes and 11 studies in rats and mice reported the use of these more human-relevant exposure routes (Figure 3). Drosophila, zebrafish, and C. elegans were the primary nonmammalian species used to investigate mechanistic aspects of Parkinson’s disease, including consequences of genetic changes and α-synuclein accumulation. As was noted with primary endpoint studies in mammals, studies on these nonmammalian species mostly evaluated locomotor activity (Figure 6). Secondary effects studies in these species might provide key mechanistic information on the potential development of Parkinson’s disease after exposures to paraquat (Figure F-2) but require follow-up studies in mammals or humans to verify relevance.

In addition to alternative whole organism models, various in vitro model systems were used to investigate the mechanisms of paraquat exposures on endpoints potentially relevant to the development of Parkinson’s disease (Figure 7). Overall, 244 in vitro studies were included at the full-text level with 68 of these studies describing the use of paraquat as a positive control used to induce oxidative stress. Of the remaining 176 studies that were investigating paraquat’s effects on cells, the general effects of cell death, oxidative stress, and mitochondrial stress were among the most measured. These studies might provide important information about how oxidative stress could contribute to Parkinson’s disease. More recently, a variety of in vitro models have been reported, including primary cell cultures and stem cells, which might include mixed cell types or genotypes from Parkinson’s disease patients and could allow for chronic exposures and more relevant endpoint measurements, such as neurite outgrowth versus cytotoxicity.

## Limitations of the Evidence Base

Key information gaps and scientific challenges were identified in the corpus of available scientific literature that describe associations between paraquat exposures and development of Parkinson’s disease. However, it should be noted that individual study quality assessment was not included in this scoping review.

Gaps and challenges identified in the human evidence include:

- Most epidemiological studies were small case-control studies with very few cases of paraquat-exposed participants, and even fewer reported or confirmed cases of Parkinson’s disease; this is particularly true for studies that might be more representative of the general population in the United States.
- Most cases of Parkinson’s disease are self-reported, prevalent cases (i.e., participants report prior diagnosis or symptoms) rather than clinician-confirmed incident cases (i.e., newly diagnosed cases). Incidence might be difficult to measure due to the progressive nature of Parkinson’s disease such that initial symptoms might go unnoticed or unreported (e.g., disrupted sleep, slight tremor).
- Females were not included in most epidemiological studies, except in the few that included spouses of agricultural workers, namely those associated with the AHS. Thus, the vast majority of reported cases were male and even population-based studies did not include female cases.
- Occupational studies included co-exposures to other pesticides and reported significant associations for one or more, including rotenone, although adjustment for co-exposures was often lacking (Furlong et al. 2015; Kamel et al. 2014; Tanner et al. 2011). Pouchieu et al. (2018) observed a significant association between paraquat and Parkinson’s disease, but this study was eliminated when the authors adjusted for co-exposure between active ingredients. Studies of environmental exposure based on the PEG cohort also had potential co-exposures to other pesticides. Studies that adjusted for exposure to other pesticides or included subjects only exposed to paraquat in the analysis did not observe an association between paraquat exposure and Parkinson’s disease.
- Exposure was mainly self-reported via questionnaires. Participants in environmental and general population studies might not be aware of paraquat exposures, and cases in retrospective studies might be prone to recall bias.

Gaps and challenges identified in the animal and in vitro evidence include:

- Animal models do not specifically develop Parkinson’s disease. Instead, deficits in dopaminergic neurons and associated neuromuscular and neurobehavioral deficits after exposures to paraquat are used to model parkinsonism.
- The paraquat exposure regimes and measured health effects endpoints varied widely across the animal and in vitro data.
- The majority of mammalian studies reported exposure to paraquat via injection, whereas humans are exposed to paraquat via dermal, oral, and inhalation routes.
- Exposure scenarios in animals might have been sufficiently high and acute, such that the effects on activity or muscle coordination might be more indicative of general toxicity than of Parkinson’s disease-like behaviors.
- Despite the challenges noted above, it is important to note that acute exposures to some compounds such as 1-methyl-4-phenyl-1,2,3,6-tetrahydropyridine (MPTP) via injections lead to parkinsonism in animals, including humans; thus, these studies might provide mechanistic information about paraquat’s potential effects and the effects of oxidative stress on dopaminergic neurons in general.
- Most in vitro studies reported the use of tumor-derived cell lines to study general stress responses.

## Limitations of the Scoping Review

Case reports or case series were not included in this review because they do not include non-exposed comparators and most describe high, acute exposures to paraquat, such as those in accidental poisonings with unclear connections to Parkinson’s disease. Although not included here, case reports might be useful for determining mechanistic insight as long as the limitations noted above are considered. For example, a case series in China reported acute exposures of subjects to paraquat mainly after suicide attempts (Wu et al. 2012). Results included significant abnormalities in the MRI scans of brains from two surviving patients with neurological symptoms, with some results still abnormal a year later.

A total of 45 reports were excluded at the full-text level because they were published in a language other than English. These reports might contain additional useful data that could contribute to a full systematic review.

It should be noted that this scoping review was limited to data from the published scientific literature. Inclusion of proprietary pesticide literature and unpublished studies were beyond the scope of this review but would potentially increase the knowledge base of any future health hazard evaluations.

## Summary

In summary, a relatively large body of evidence was identified that collectively describes the potential association between paraquat exposure and Parkinson’s disease. Several recommendations can be drawn from this evidence to inform future research. Future epidemiological studies could include biomonitoring of specific pesticide exposures to separate paraquat’s effects from those of other chemicals and mixtures. Inclusion of higher numbers of paraquat-exposed and incident Parkinson’s disease cases from the general population (including women exposed to paraquat and/or with symptoms of Parkinson’s disease) would allow findings to be further generalized beyond occupational settings. To increase the direct relevance of experimental animal studies to human Parkinson’s disease, future laboratory animal studies could include administration of paraquat via a route that is more relevant to the general human population (oral or inhalation) and include measurement of neuromuscular or neurobehavioral endpoints and direct counts of dopaminergic neurons. Investigating the effects of longer-term paraquat exposures in vitro on endpoints with clear linkages to Parkinson’s disease (such as loss in neuron numbers and accumulation of α-synuclein) in primary human cell models might provide critical mechanistic information linking these exposures to neurological deficits observed in humans and animals.

This scoping review along with associated online interactive figures and visualizations were used to support an ongoing systematic review of paraquat and Parkinson’s disease as part of a registration review of paraquat dichloride by EPA OPP (Docket ID EPA-HQ-OPP-2011-0855 (https://www.regulations.gov/docket?D=EPA-HQ-OPP-2011-0855)).