# Results

## Literature Search Results

The screening results and reasons for exclusion are outlined in the study selection diagram (Figure 1). The electronic database searches retrieved 8,685 references, which resulted in 7,042 after duplicate removal. Review of reference lists of relevant published review articles yielded an additional 1,329 articles, which resulted in 124 references after duplicate removal. Thus, a total of 7,166 individual references were screened for relevance and eligibility in the title-and-abstract screen. Of these, 6,152 studies were excluded as not relevant to PECO and 120 records had no primary data, such as review articles and commentaries. This resulted in 894 studies reviewed in the full-text screen, of which 426 were excluded as not relevant to PECO along with 10 reviews, leaving 458 total included studies after screening (Figure 1). Five included articles were identified by the review of reference lists rather than through electronic database searches: three human primary-endpoint studies, one animal secondary study, and one in vitro study.

### Human Health-relevant Studies

Figure 1 illustrates the breakdown of included studies by evidence stream and primary or secondary data. A total of 25 human epidemiological studies (24 primary endpoint studies and 1 secondary endpoint study) were identified that satisfied the PECO inclusion criteria along with 143 experimental animal studies reporting primary endpoints, 190 experimental animal studies reporting secondary endpoints, and 244 in vitro studies. Because some included studies reported data from multiple evidence streams or both primary and secondary outcomes, these numbers do not add up to the total number of studies considered relevant (i.e., 458). A list of included studies after full-text review is itemized in [underlined: Appendix E] of this scoping review report and high-level summaries of studies within each evidence stream (i.e., human, experimental animal, and in vitro) are provided in the following sections.

#### Human Studies

The epidemiological studies that evaluated the association between paraquat exposure and primary outcomes of Parkinson’s disease, including Parkinson’s disease diagnosis or clinical symptoms of parkinsonism, consisted of analysis of incidence in a prospective cohort study, 3 cross-sectional analyses of prevalence in this prospective cohort, 19 case-control studies, a retrospective cohort study, and an ecological study (Figure F-1). Many related publications or follow-up analyses were based on the same study populations as described in more detail in the following sections. All studies evaluated Parkinson’s disease, although researchers defined and captured the outcomes differently, most commonly by self-report of diagnosis, but also by clinical observations of neurological effects associated with parkinsonism. Two studies reporting unique outcome assessment approaches included a retrospective cohort that evaluated mortality in workers at a paraquat manufacturing plant (Tomenson and Campbell 2011) and one that investigated the onset of Parkinson’s disease (i.e., before or after the age of 68) in residents living near agriculture areas in California (Gatto et al. 2010). The majority of the studies (n = 17) were conducted in the United States; others were conducted in the Netherlands, France, Canada, Taiwan, and the United Kingdom.

Epidemiological studies were grouped by potential levels of exposure using the following exposure types as proxies for levels of exposure: (1) occupational studies that included pesticide applicators, farmers, and others who used paraquat on the job and were estimated to be exposed to the highest levels of paraquat (Table 2; Figure F-2); (2) environmental exposure studies in which residences and/or workplaces of participants were near agricultural areas or other situations with moderate paraquat exposure levels (Table 3; Figure F-3); and (3) general population studies that were more representative of typical exposures to people who do not work directly with paraquat or live in areas associated with higher usage of paraquat, although these studies might include subjects who used paraquat at work (Table 4; Figure F-4). Brief descriptions of epidemiological studies are provided in the following sections to provide an overview of the key studies and results.

Table 2 Epidemiological Studies Evaluating Occupational Paraquat Exposure and Parkinson’s Disease

Country; State/Region | Study Population | Study Design (n) | Exposure Assessment | Outcome Assessment | Results | Study
United States; Iowa and North Carolina | Pesticide workers and spouses in Agricultural Health Study cohort | Prospective cohort (incidence: 78 cases [11 exposed], 55,931 controls [7,382 exposed]) Cross-sectional (prevalence: 83 cases [14 exposed], 79,557 controls [11,266 exposed]) | Ever exposed to paraquat based on self-reporting of duration and frequency of pesticide use, as well as, ever used paraquat | Parkinson’s disease (incidence and prevalence) Self-reporting of doctor-diagnosed Parkinson’s disease | ns adjOR for ever use of paraquat (incidence) ↑ adjOR for ever use of paraquat (prevalence) | (Kamel et al. 2007)
United States; Iowa and North Carolina | FAME participants^a^ | Case-control (110 cases [23 exposed], 358 controls [49 exposed]) | Ever exposed to paraquat based on computer-assisted telephone interviews to obtain detailed information on pesticide use from age 14 onward | Parkinson’s disease Diagnosis determined by agreement of two neurologists after independent review of all available diagnostic information | ↑* adjOR for ever use of paraquat | Tanner et al. (2011)
United States; Iowa and North Carolina | FAME participants^a^ | Case-control (87 cases [21 exposed], 343 controls [52 exposed]) | Estimated exposure using computer-assisted telephone interviews to determine ever use of paraquat and cumulative lifetime years of use | Parkinson’s disease Diagnosis determined by consensus of two movement disorder specialists using all available information and applying NINDS/UK Brain Bank criteria | Paraquat use (Y/N): ↑* adjOR for ever use of paraquat Paraquat use (years–lifetime): ↑^ǂ^ adjOR for ever use of paraquat (≤4 years) ↑^ǂ^ adjOR for ever use of paraquat (>4 years) Homozygous deletion genotype for GSTT1: ns adjOR for paraquat exposure by genotype (9 exposed cases with deletion, 6 exposed controls with deletion), but there was a significant interaction between paraquat exposure and genotype | Goldman et al. (2012)
United States; Iowa and North Carolina | FAME participants^a^ | Case-control (89 cases [18 exposed, males only], 336 controls [46 exposed, males only]) | Occupational exposure to paraquat was assessed via telephone interview; interviewers collected a complete occupational history and information on pesticide use from age 14 onward | Parkinson’s disease Self-reported cases evaluated by neurologists during home visits; diagnosis determined by agreement of two movement disorder specialists using medical records and the in-home evaluation | ↑* adjOR for paraquat exposure with low total fat diet ↑* adjOR for paraquat exposure with high saturated fat diet | Kamel et al. (2014)
United States; Iowa and North Carolina | FAME participants^a^ | Case-control (69 cases [22 exposed], 237 controls [48 exposed]) | Estimated exposure based on complete occupational history to evaluate paraquat exposure in each job held from age 14 to reference data; determination of hygiene practices and personal protective equipment use was also self-reported | Parkinson’s disease Case status determined by agreement of two movement disorder specialists following established criteria and using information from medical records and the in-home evaluation; diagnosis dates determined from medical histories | Paraquat use: ↑* adjOR for ever use of paraquat Based on hygiene practices ↑* adjOR for paraquat (glove use ≤50% based on several different models) | Furlong et al. (2015)
United States; Washington | Pesticide workers who were previous participants in a Washington State Department of Health cohort during 1972–1976 (US EPA 1976) | Cross-sectional (310 workers [238 with exposure to paraquat and 72 unexposed controls matched for similar physical activity levels in their occupation]) | Estimated exposure based on self-administered questionnaire on occupational pesticide use throughout their working career and years of use | Parkinsonism Diagnosed based on neurological examination by a trained nurse; defined as the presence of two or more of the following signs: bradykinesia, rest tremor, rigidity, and impairment of postural reflexes | ns adjPR for paraquat exposure, tertile years of exposure, and acre-years | Engel et al. (2001)
North America; 7 in United States and 1 in Canada | Parkinson’s patients and hospital controls from 8 centers | Case-control (519 cases [9 exposed], 511 controls [4 exposed]) | Ever exposed was assessed based on occupational history information for all jobs held for at least 3 months acquired via computer-assisted telephone interview | Parkinson’s disease Diagnosed by the enrolling investigator based on clinical features and Unified Parkinson’s Disease Rating Scale score | ns adjOR for paraquat exposure (large OR, but not significant due to wide CI) | Tanner et al. (2009)
Canada; Okanagan Valley, British Columbia | Residents in horticultural region | Case-control (127 cases [6 exposed], 245 controls [5 cardiac disease controls exposed, 4 voter controls exposed]) | Exposure to paraquat assessed via questionnaire; exposure defined as handling paraquat or working in an area that had been recently sprayed | Idiopathic parkinsonism Diagnosed by a neurologist based on patients having two of the following symptoms: resting tremor, rigidity, bradykinesia, and loss of postural reflexes | ns adjOR for paraquat exposure (cardiac disease controls) ns adjOR for paraquat exposure (voter controls) | Hertzman et al. (1994)
France | Agriculture workers in Agriculture and Cancer cohort | Cross-sectional^b^ (149,810 participants, Parkinson’s disease reported in 1,732 participants; 244 cases exposed and 25,298 non-cases exposed) | Exposure was assessed using the French crop-exposure matrix PESTIMAT, which reconstitutes pesticide use since 1950 in the main crops | Parkinson’s disease Self-reporting of doctor-diagnosed Parkinson’s disease, age range at diagnosis, and having at least two parkinsonian symptoms (tremor in hands or feet; rigidity of arms or legs; slowness or tightening in daily living, walking, or speaking) | ns adjOR for paraquat exposure (1–25 years) ns adjOR for paraquat exposure (26–46 years) ns adjOR for ever paraquat exposure (when adjusted for co-exposure between active ingredients) | Pouchieu et al. (2018)
United Kingdom; Widnes | Paraquat production workers | Cohort (retrospective) (968 workers [1 case of Parkinson’s disease]) | Workers at a paraquat manufacturing plant in Widnes; although there were some monitoring data, there was insufficient sampling information available to perform a quantitative exposure assessment | Parkinson’s disease (cause of death) Diagnosed based on review of death certificate | No significant change in standardized mortality ratio either with Parkinson’s disease mentioned as cause of death or as an underlying cause of death | Tomenson and Campbell (2011)
The Netherlands | Parkinson’s patients and controls from 5 hospitals | Case-control (444 cases [33 exposed], 876 controls [58 exposed]) | Exposure estimated to specific active ingredient by linking self-reported crops cultivated at the subject’s farm to a crop-exposure matrix | Parkinson’s disease Medical files reviewed by neurologist to confirm case diagnosis | ns adjOR for exposure based on median of the distribution of the different exposures among controls | van der Mark et al. (2014)

FAME = farming and movement evaluation; adjOR = adjusted odds ratio; adjPR = adjusted prevalence rate; CI = confidence interval; ns = no change; ↑ = increase; ↑* = significant increase; ↑^ǂ^ = significant trend.

^a^ Studies examining FAME participants were nested case-control studies.

^b^ Agriculture and Cancer is a prospective cohort, but results were from the baseline questionnaire only; therefore, the study is considered a cross-sectional analysis.

Additional study details available in Figure F-2.

Table 3 Epidemiological Studies Evaluating Environmental Paraquat Exposure and Parkinson’s Disease

Country; State/Region | Study Population | Study Design (n) | Exposure Assessment | Outcome Assessment | Results | Study
United States; California | Parkinson’s Environment and Genes Study (PEG) participants Central Valley, CA residents | Case-control (368 cases [149 paraquat only], 341 controls [152 paraquat only]) | Average annual exposure estimated using self-reported residence and workplace address histories combined with pesticide use data from California Department of Pesticide Regulation and land use maps from California Department of Water Resources | Parkinson’s disease Diagnosed based on examination by a UCLA movement disorder specialist and confirmation of clinically probable or possible Parkinson’s disease | [underlined: Exposure status (1974–1999):] ns adjOR for paraquat-only exposure | Costello et al. (2009)
United States; California | PEG participants Central Valley, CA residents | Case-control (368 cases [79 exposed], 341 controls [60 exposed]) | Estimated ambient exposure for historical residential addresses inhabited between 1974 and 1999 using GIS modeling; exposure from private well water was estimated based on a combination of pesticide use and application data and self-reports of private wells as drinking water sources at a residential address | Parkinson’s disease Diagnosis of clinically probable or possible Parkinson’s disease cases confirmed by UCLA movement disorder specialist based on 5 criteria related to parkinsonian syndrome | ns adjOR for any of the paraquat exposure | Gatto et al. (2009)
United States; California | PEG participants Central Valley, CA residents | Case-control (333 cases, 336 controls [number of exposed ranged from 4 to 105, depending on exposure {high}, age of onset, and genotype]) | Estimated ambient exposure from pesticide application to agricultural crops using a GIS-based exposure assessment tool using geocoded lifetime address data, historical pesticide use data from the California Department of Pesticide Regulation, and land use data | Parkinson’s disease Diagnosis of incident idiopathic Parkinson’s disease confirmed by UCLA movement disorder specialists | No significant changes in adjusted OR, but trend for increased OR with high paraquat exposure, with onset of Parkinson’s disease ≤68 years old, and with α-synuclein variations | Gatto et al. (2010)
United States; California | PEG participants Central Valley, CA residents | Case-control (362 cases [81 workplace, 109 residential paraquat-only], 341 controls [78 workplace, 125 residential paraquat only]) | Average annual exposure estimated using residence and workplace address histories combined with pesticide use data from California Department of Pesticide Regulation and land use maps from California Department of Water Resources | Parkinson’s disease Diagnosed based on examination by a UCLA movement disorder specialist and confirmation of clinically probable or possible Parkinson’s disease | [underlined: Workplace exposure status:] ns adjOR for paraquat exposure [underlined: Residential exposure status:] ns adjOR for paraquat exposure | Wang et al. (2011)
United States; California | PEG participants Central Valley, CA residents Subjects are the same as those reported in Costello et al. (2009) | Case-control (357 cases [169 exposed], 754 controls [291 exposed]) | Average annual exposure estimated using residence and workplace address histories combined with pesticide use data from California Department of Pesticide Regulation and land use maps from California Department of Water Resources | Idiopathic Parkinson’s disease Diagnosed by UCLA movement disorder specialists | ↑* adjOR for ambient residential and workplace exposures | Lee et al. (2012)
United States; California | PEG participants Central Valley, CA residents | Case-control (619 cases [245 exposed], 854 controls [296 exposed]) | Ambient exposure was estimated using a GIS model combined with pesticide use data and land use maps from California | Parkinson’s disease Clinical confirmation of Parkinson’s diagnosis by a UCLA movement disorder specialist | ↑* adjOR for ambient residence and workplace paraquat exposure [underlined: Paraquat exposure by genotype:] ↑* adjOR for high exposure only with 2 risk genotypes (significant interaction) | Sanders et al. (2017)

OR = odds ratio; adjOR = adjusted odds ratio; ns = no change; ↑ = increase; ↑* = significant increase.

Additional study details available in Figure F-3.

Table 4 Epidemiological Studies Evaluating Paraquat Exposure and Parkinson’s Disease in the General Population

Country; State/Region | Study Population | Study Design (n) | Exposure Assessment | Outcome Assessment | Results | Study
United States; Nebraska | Residents of Nebraska | Ecological (6,557 cases [numbers of exposed in each quartile not reported]) | Estimated from GIS modeling using combination of land use data, pesticide usage databases, and historical pesticide use surveys | Parkinson’s disease Spatial analysis of Parkinson’s disease—exposure associations based on statewide population-based Parkinson’s disease registry | Higher risk of Parkinson’s disease in Q3 (medium-high) and Q4 (high) exposure to paraquat compared with Q1 (low exposure group), but trend for risk was not significant (i.e., Q4 risk was not higher compared with Q3) | Wan and Lin (2016)
United States; Texas | Parkinson’s patients and controls from East Texas neurology practice | Case-control (100 cases [4 exposed], 84 controls [1 exposed]) | Exposure estimated from self-reported lifetime use of paraquat | Parkinson’s disease Diagnosed by a neurologist specializing in movement disorders based on standard clinical/lab diagnostic criteria | ns OR for ever personally used/mixed or applied paraquat (large OR, but not significant due to wide CI) | Dhillon et al. (2008)
United States; Washington | Group Health Cooperative (GHC) of Washington State | Case-control (250 cases [2 exposed], 388 controls [2 exposed]) | Paraquat exposure was based on self-reported occupational and home-based pesticide use during structured interview; occupational pesticide exposure based on checklist of common chemical agents, whereas home-based pesticide exposure was based on a checklist of commercial brand name products (paraquat was listed under chemicals for occupational exposure, but not specifically listed for home-based use) | Parkinson’s disease Cases identified using provider referrals and computerized databases; Parkinson’s disease diagnoses confirmed by a neurologist via medical chart review, requiring at least 2 of 4 signs of Parkinson’s disease: bradykinesia, resting tremor, cogwheel rigidity, postural reflex impairment | [underlined: Paraquat exposure vs. no exposure:] ns adjOR for any paraquat exposure | Firestone et al. (2005)
United States; Washington | GHC of Washington State | Case-control (404 cases, 526 controls; 252 male cases [2 exposed], 326 male controls [3 exposed]; 152 female cases [0 exposed], 200 female controls [0 exposed]) | Paraquat exposure was based on self-reported workplace exposure to various toxicants from a checklist of other things including paraquat | Parkinson’s disease Cases identified using provider referrals or computerized databases; a panel of neurologists confirmed Parkinson’s disease diagnoses by medical chart review, requiring at least 2 of 4 signs of Parkinson’s disease: bradykinesia, resting tremor, cogwheel rigidity, postural reflex impairment | [underlined: Paraquat exposure vs. no exposure:] ns adjOR for any paraquat exposure in males; OR could not be calculated for females | Firestone et al. (2010)
British Columbia | Parkinson’s patients and controls from a mountainous rural area | Case-control (57 cases [4 exposed], 122 controls [0 exposed]) | Exposure estimated based on self-reporting of private well-water use, occupational history, and past chemical handling (e.g., question asked ever handled paraquat) | Parkinson’s disease Based on physician reporting of Parkinson’s disease patients under their care and a follow-up neurologist examination | No OR could be calculated | Hertzman et al. (1990)
The Netherlands | Parkinson’s patients and controls from five hospitals | Case-control (352 cases [181 exposed], 607 controls [322 exposed]) | Exposure estimated using a spatio-temporal model to assign environmental pesticide exposure to residential addresses (based on crop cultivation within 100 m of the residence, then split into two different distance categories 0–50 m and >50–100 m) | Parkinson’s disease Medical files reviewed by neurologist to confirm case diagnosis | ns adjOR for ever exposure to paraquat or by tertile regardless of distance category | Brouwer et al. (2017)
Taiwan, Province of China; Taipei | Parkinson’s patients and hospital controls | Case-control (120 cases [31 exposed], 240 controls [22 exposed]) | Exposure estimated based on self-reporting of residential and farming history, drinking water sources, and pesticide use/exposure (subjects were asked to identify specific herbicides/pesticides and chemicals they had used) | Parkinson’s disease Diagnosed at the Movement Disorder Clinic of National Taiwan University Hospital, based on 2 or more cardinal signs of Parkinson’s disease: resting tremor, cogwheel rigidity, bradykinesia, postural reflex instability, responsiveness to levodopa therapy | ↑* OR for ever paraquat use ↑* adjOR for paraquat use >20 years | Liou et al. (1997)

OR = odds ratio; adjOR = adjusted odds ratio; CI = confidence interval; ns = no change; ↑ = increase; ↑* = significant increase.

Additional study details available in Figure F-4.

##### Occupational Studies

The Agricultural Health Study (AHS) is a prospective cohort study of more than 50,000 licensed pesticide applicators and more than 30,000 of their spouses living in North Carolina and Iowa in the United States ([underlined: https://www.aghealth.nih.gov/about/]). All AHS participants are asked at enrollment, and at 5-year follow-up evaluation, to report whether they had ever been diagnosed with Parkinson’s disease by a physician and at what age they were first diagnosed. A subset of participants completed a supplemental questionnaire that included additional information on paraquat and other pesticides suspected to be associated with Parkinson’s disease (Kamel et al. 2007). An increase in odds ratio that was not statistically significant was observed for prevalent cases of Parkinson’s disease (83 subjects who reported physician-diagnosed Parkinson’s disease at enrollment; adjusted odds ratio [adjOR] 1.8; 95% confidence interval [CI] 1.0–3.4) for the paraquat-exposed workers, but not with incident cases (78 reported diagnosis during follow-up; adjOR 1.0; 95% CI 0.5–1.9) (Figure F-2).

Most of the self-reported Parkinson’s disease cases were subsequently invited to participate in the Farming and Movement Evaluation (FAME) studies, which were nested case-control studies within AHS that confirmed self-reported Parkinson’s disease cases by follow-up assessments, including clinical evaluation of movement disorders and completion of additional exposure assessment questionnaires designed to capture lifetime paraquat exposures (Tanner et al. 2011). All four FAME studies that were included as relevant to this scoping review (i.e., evaluated exposure to paraquat alone) reported significant increases in odds ratio for prevalent Parkinson’s disease with paraquat exposure (Furlong et al. 2015; Goldman et al. 2012; Kamel et al. 2014; Tanner et al. 2011) (Figure F-2). Compared with participants who had never applied paraquat (n = 396 unexposed; 87 of 110 cases and 309 of 358 controls), pesticide applicators who had been exposed to paraquat (n = 72; 23 of 110 cases and 49 of 358 controls) were at a higher risk of Parkinson’s disease (adjOR 2.5; 95% CI 1.4–4.7) (Tanner et al. 2011). An even greater risk of Parkinson’s disease was observed in pesticide applicators with a homozygous GSTT1 deletion who had been exposed to paraquat, although the number of exposed cases and controls were fewer (adjOR 11.1; 95% CI 3.0–44.6; n = 9 exposed cases and 6 exposed controls with deletion) (Goldman et al. 2012). In addition, a higher odds ratio for Parkinson’s disease was observed with longer duration of paraquat exposure in those with a homozygous GSTT1 deletion (Goldman et al. 2012). Furlong et al. (2015) reported a greater risk in workers who used gloves ≤50% of the time (adjOR 3.9; 95% CI 1.5–10.2) than in those who used gloves more consistently (adjOR 1.6; 95% CI 0.6–4.2). Finally, Kamel et al. (2014) observed a higher risk with exposure to paraquat in subjects with low total dietary fat consumption (adjOR 4.7; 95% CI 1.7–12.6) compared with those who consumed higher total levels of fat in their diets (adjOR 1.4; 95% 0.5–3.7). The increase in Parkinson’s disease risk with low-fat diets was related to lower consumption of unsaturated fats, including monounsaturated fatty acids (MUFAs; adjOR 3.8; 95% CI 1.4–10.4), polyunsaturated fatty acids (PUFAs; adjOR 4.2; 95% CI 1.5–11.6), and linoleic acid (adjOR 3.8; 95% CI 1.4–10.3). The paraquat exposure in subjects with a high-fat diet was significant when focusing on saturated fats only (adjOR 3.1; 95% CI 1.2–8.0).

The Agriculture and Cancer (AGRICAN) cohort is another large prospective cohort that follows active and retired agricultural workers from France. Researchers conducted a cross-sectional analysis using the AGRICAN enrollment questionnaire and reported a significant increase in prevalence of self-reported diagnosis of Parkinson’s disease at enrollment in subjects exposed to paraquat (adjOR 1.43; 95% CI 1.17–1.75), but this increase was eliminated after adjusting for co-exposures to active ingredients of other pesticides (adjOR 1.01; 95% CI 0.41–2.49) (Pouchieu et al. 2018). An increase in odds ratio by duration in years compared with unexposed subjects was observed; however, the results were not statistically significant.

Other studies in subjects exposed occupationally to paraquat did not observe significant associations between paraquat exposure and Parkinson’s disease. Similar to the FAME analyses, these studies reported few cases of the disease and many involved co-exposures to other pesticides. Tanner et al. (2009) evaluated occupations, including pesticide use among farmers, as a risk factor for Parkinson’s disease in North America. Paraquat exposure occurred in 9 of the 519 cases and 4 of the 511 controls; however, 6 of the 13 subjects exposed to paraquat were also exposed to other pesticides. A cross-sectional analysis of 310 workers (238 with exposure to paraquat and 72 unexposed controls matched for similar physical activity levels in their occupations) selected from participants of a previous cohort study conducted by the Washington State Department of Health from 1972 to 1976 found no significant associations between paraquat exposure and parkinsonism based on prevalence ratios (estimated using a general linear model due to high prevalence of parkinsonism among participants) categorized by exposed versus unexposed, tertile of years of exposure, or tertile of acre-years of exposure (Engel et al. 2001). Outcome assessment consisted of confirmed clinical symptoms of parkinsonism rather than Parkinson’s disease diagnosis; notably, only one participant self-reported a diagnosis of Parkinson’s disease. A retrospective cohort of workers in a paraquat manufacturing plant did not find an increase in mortality from Parkinson’s disease, as only 1 of 307 total deaths identified the disease as the underlying cause of death (Tomenson and Campbell 2011). Similarly, in a case-control study in British Columbia, occupational paraquat exposure did not significantly increase the risk of idiopathic parkinsonism using cardiovascular disease patients as controls (adjOR 1.11; 95% CI 0.32–3.87; 6 cases, 5 controls) or voters as controls (adjOR 1.25; 95% CI 0.34–4.63; 6 cases, 4 controls) (Hertzman et al. 1994). A hospital-based case-control study in the Netherlands did not find a significant association between paraquat exposure and Parkinson’s disease using a crop-exposure matrix based on both self-reported exposure and corrected, active-ingredient exposure (van der Mark et al. 2014).

A single occupational exposure study reported the secondary outcome oxidative stress (Ranjbar et al. 2002). Oxidative stress was evaluated in paraquat formulation workers and compared with age-matched volunteers from Tehran University with no direct pesticide exposure. Paraquat workers had higher levels of plasma lipid peroxidation and lower levels of plasma antioxidant capacity and thiol levels. This study was not included in any summary figures or tables as it did not contain primary outcome data.

##### Environmental and General Population Studies

For this review, the epidemiological studies that did not specifically investigate occupational exposures were divided into environmental exposures where locations of residences or workplaces might be expected to contain moderate levels of paraquat (Table 3) and those with paraquat exposures representative of the general population with the lowest levels of paraquat exposures expected (Table 4). Few significant associations were observed in the studies classified in either of these categories (Figure F-3 and Figure F-4). The Parkinson’s Disease, Environment, and Gene (PEG) Study recruited participants between 2001 and 2007 and between 2010 and 2015 and assessed the potential relationship between environmental susceptibility (including exposure to pesticides such as paraquat) and genetics in rural Parkinson’s disease patients. The PEG study used a population-based approach to identify Parkinson’s disease cases in three counties (Fresno, Tulare, and Kern) of California. Six resulting articles evaluated the association between paraquat exposure and Parkinson’s disease in participants from the study. It was not clear in every case whether the report was officially a PEG study because some reports noted that cases were enrolled in the PEG study, whereas others cited a common reference for methods (Kang et al. 2005) but did not refer to the PEG study by name. The majority of these studies did not observe significantly higher adjusted odds ratios with paraquat exposure (Costello et al. 2009; Gatto et al. 2009; Gatto et al. 2010; Wang et al. 2011). Although Gatto et al. (2010) did not report any significant findings with paraquat exposure, adjusted odds ratios tended to increase with higher paraquat exposure for those subjects with onset of Parkinson’s disease at ≤68 years old, and with α-synuclein gene variations (adjOR 3.15; 95% CI 0.74–13.37). Indications of increased risk with paraquat exposure were reported in some PEG studies. Lee et al. (2012) evaluated ambient residential and workplace exposures to paraquat and observed a significant increase in risk (adjOR 1.36; 95% CI 1.02–1.81). High paraquat exposures at residences or workplaces in subjects containing two risk genotypes (i.e., base excision repair single nucleotide polymorphisms in APEX1 and OGG1 genes) were observed to significantly increase risk (Sanders et al. 2017).

Two other studies in locations other than California found significant associations between paraquat exposure and Parkinson’s disease. In a study in Taiwan evaluating environmental risk factors for Parkinson’s disease, duration of paraquat use of >20 years was associated with a significant increased risk (adjOR 6.44; 95% CI 2.41–17.2) (Liou et al. 1997). An ecological study cross-referenced a statewide registry of patients diagnosed with Parkinson’s disease in Nebraska with land use and pesticide exposure databases to perform a spatial analysis of paraquat exposure levels and risk of Parkinson’s disease (Wan and Lin 2016). While the two highest quartiles of paraquat exposures were associated with higher risk than the lowest quartile, the risk did not increase significantly between the two highest exposure groups (i.e., the response did not increase in a concentration-dependent manner).

#### Animal Studies

Animal models do not develop Parkinson’s disease per se and instead were categorized by neurocognitive effects that might be expected to correlate with parkinsonism symptoms in humans including primary effects such as motor activity, motor coordination, motor skills, number of dopaminergic neurons (i.e., number of tyrosine hydroxylase-positive [TH+] neurons), as well as other cognitive effects such as anxiety and memory. Secondary effects included mechanistic data such as levels of dopamine, density of TH immunoreactivity, or other biochemical changes associated with Parkinson’s disease, as well as general effects to the nervous system such as measurements of oxidative stress levels.

A total of 143 experimental studies in laboratory animals were identified as measuring primary endpoints and 190 as measuring secondary endpoints (Figure 1); 119 studies reported both primary and secondary endpoints. Primary endpoints were measured in 113 mammalian studies (Figure 2). A variety of neurological effects were investigated, including 66 studies that estimated the number of dopaminergic cells by measuring the number of TH+ neurons. Changes in locomotor activity were the most often reported neurobehavioral effects, including locomotion (34 studies) and distance traveled (6 studies) followed by effects on motor skills (34 studies). Some studies reported qualitative results that were not eligible for quantitative data extraction but might provide relevant information about the link between paraquat exposure and parkinsonism (e.g., descriptive histopathology of the brain in 13 studies). The majority of the animal studies with endpoints specific for parkinsonism did not report administration of paraquat via a route that would be relevant to human exposures (i.e., oral, dermal, or inhalation) with 83 of the 113 studies using intraperitoneal injection and most others using subcutaneous or other methods of administration (including intracranial in a couple of cases) (Figure 2).

Figure 2

Number of Studies That Evaluated Primary Effects Following Paraquat Exposures in Mammalian Models

Numbers indicate the counts of studies that have investigated the identified endpoints; no indication of direction or significance of effect is provided. Some studies might have characterized multiple health effects or multiple routes of exposure and therefore could be listed multiple times. Row and column totals and grand total shown in the figure represent counts of distinct references. The endpoint movement: locomotion under Muscular Effects and the endpoint behavior: exploratory under Psychomotor Effects are interlinked and sometimes measured using the same open field test. However, exploratory behavior is used for endpoints that measured a specific behavior that reflected more than simple locomotor movement. This may include specific patterns of movement or other designations of exploration given by study authors.

Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-RR-16) (NTP, 2019b).

##### High External Validity Study Designs

Because humans are exposed to paraquat through diet or direct contact via inhalation or skin, study designs that administered paraquat through these routes and measured primary effects in mammals were considered to be the most informative to human exposure scenarios and Parkinson’s disease (i.e., high external validity). Eleven studies in rats and mice reported administration of paraquat via dermal (n = 1), oral (n = 9), inhalation (n = 0), and intranasal (n = 1) exposures and evaluated a primary health effect, with most measuring neuromuscular effects including locomotor activity, motor skills, and cognitive behavior (Figure 3). Several studies using orally exposed rats or mice reported data for secondary animal effects and will be discussed in the following section on secondary effects.

Figure 3

Number of Studies and Direction of Effect for Primary Animal Effects Evaluated Following Oral, Dermal, or Inhalation Paraquat Exposures in Mammalian Models

Some studies might have characterized multiple health effects and therefore could be represented multiple times. Row and column grand totals represent counts of distinct references. The endpoint movement: locomotion under Muscular Effects and the endpoint behavior: exploratory under Psychomotor Effects are interlinked and sometimes measured using the same open field test. However, exploratory behavior is used for endpoints that measured a specific behavior that reflected more than simple locomotor movement. This may include specific patterns of movement or other designations of exploration given by study authors.

Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-RR-16) (NTP, 2019b).

Study data for these 11 studies are available on HAWC (https://hawcproject.org/assessment/475/) (NTP, 2019a).

Comparing across these studies, paraquat was reported to elicit neuromuscular effects more often in mice relative to rats. Two oral gavage studies in mice evaluated locomotor activity and observed decreases in activity (Fredriksson et al. 1993; Ren et al. 2009). Both studies used C57BL/6 mice, but the doses differed: Fredriksson et al. (1993) administered 0.07 and/or 0.36 mg/kg over two days depending on the age of the mice and Ren et al. (2009) administered 10 mg/kg/day for 4 months. A third oral gavage study noted effects on learning and spatial memory in C57BL/6 mice, as indicated by an increase in escape latency in the probe test of the Morris water maze (Lou et al. 2016). This study, however, evaluated latency to find the platform, which could have been affected by motor activity and was not discussed, even though some animals died. Chen et al. (2010) evaluated learning and spatial memory in Kunming mice using the Morris water maze. Mice were exposed to 0.89, 2.67, or 8 mg/kg/day via oral gavage, and the study reported both an increased latency to reach the platform (on multiple training days) and a decrease in the number of times passing the platform (as part of the spatial probe test). The study did not report whether motor activity was affected, nor any mortality or clinical signs in the animals. An oral gavage dose of 20 mg/kg/day to male Swiss mice was found to cause a significant change in motor skills as indicated by decreased latency to fall from the rotarod test (Satpute et al. 2017). Doses of 10–20 mg/kg/day in drinking water did not have significant effects on motor skills in female C57BL/6 mice (Naudet et al. 2017), or male wild-type CuZnSOD mice when tested at 4 months or 2 years of age (Peled-Kamar et al. 1997). Two studies investigated the number of TH+ neurons in C57BL/6 mice but did not report a significant change with doses up to 21.5 mg/kg/day in females exposed via diet for 13 weeks (Minnema et al. 2014) or male mice exposed to 20 mg/kg/day via intranasal inoculation for 30 days (Rojo et al. 2007) (Figure 3).

No significant effects on motor skills were noted in male AP rats orally exposed to 5 mg/kg/day paraquat (Widdowson et al. 1996). Dermal administration of 40 mg/kg/day paraquat to female Wistar rats did not cause a significant change in locomotor activity, but did decrease motor skills as measured by climbing on blocks less frequently (Luty et al. 1997). Luty et al. (1997) also observed no differences in exploration, as measured by interest in blocks, or anxiety, as measured by washing and defecations, in female Wistar rats dermally administered 40 mg/kg/day for 28 days. However, interest in blocks and defecations significantly decreased after 14 days of treatment (note: defecations were also lower prior to paraquat exposure). Two additional studies in rats that administered paraquat via relevant exposure routes reported qualitative histopathology only and were not displayed in the figures (Caroleo et al. 1996; Li et al. 2015).

##### Secondary Effects in Mammals

Effects that were classified as secondary effects included indirect measures of dopaminergic neurons, modifications of α-synuclein levels, mitochondrial dysfunction, and general measures of oxidative stress (Figure 4 and Figure 5). Of the 11 studies in rats and mice that administered paraquat via exposure routes relevant to human exposures (dermal, oral, inhalation, and intranasal), 9 also assessed relevant secondary animal effects. An additional 5 studies using relevant exposure routes evaluated secondary animal effects only and are included in Figure 4 for a total of 14 studies. Oxidative stress parameters were examined in rats and mice, along with changes in levels of dopamine, dopamine metabolites, and other neurotransmitters. Glial or astrocyte activity, as well as alpha-synuclein and expression of glial fibrillary acidic protein, were also described in mice. Other endpoints evaluated included mitochondrial dysfunction and lipid peroxidation.

Figure 4

Number of Studies That Evaluated Secondary Animal Effects Following Oral, Dermal, or Inhalation Paraquat Exposures in Mammalian Models

Numbers indicate the counts of studies that have investigated the identified endpoints; no indication of direction or significance of effect is provided. Some studies might have characterized multiple health effects or species and therefore could be represented multiple times. Row and column grand totals represent counts of distinct references.

Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-RR-16) (NTP, 2019b).

Figure 5

Number of Studies That Evaluated Secondary Animal Effects Following Paraquat Exposures via Other Routes in Mammalian Models

Numbers indicate the counts of studies that have investigated the identified endpoints; no indication of direction or significance of effect is provided. Some studies might have characterized multiple health effects or species and therefore could be represented multiple times. Row and column grand totals represent counts of distinct references.

Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-RR-16) (NTP, 2019b).

Studies using exposure routes less relevant to humans also evaluated a wide variety of secondary endpoints in various mammalian models (Figure 5). Rats and mice were the most-studied species with the majority of rodent studies focused on effects on dopamine, gene expression, and oxidative stress. Other more general mechanisms such as oxidative stress and changes in genes or protein levels have also been evaluated following paraquat exposure. However, as was observed with the primary effects, the route of exposure for most of these studies was injection (interactive Figure 5 (NTP, 2019b)).

##### Alternative Model Organisms

Several nonmammalian organisms have also been used as models to investigate paraquat exposures to primary outcomes (Figure 6) and secondary outcomes (Figure F-5), modeling some aspects of Parkinson’s disease. Similar to the rodent studies discussed earlier, the specific endpoints used to measure paraquat effects in these studies vary between species and studies, but the most-often-studied primary endpoint category was locomotor activity (Figure 6). With 20 studies describing the primary effects of paraquat on Drosophila, the species has been used as a model for Parkinson’s disease. These studies often investigated genetic changes reported to be associated with Parkinson’s disease with climbing being the primary measured effect on locomotor activity. Ten studies evaluated primary effects in other nonmammalian species, including zebrafish and Caenorhabditis elegans. The main primary endpoint category in these models was also locomotor activity (Figure 6).

Figure 6

Number of Studies That Evaluated Primary Animal Effects Following Paraquat Exposures in Nonmammalian Models

Numbers indicate the counts of studies that have investigated the identified endpoints; no indication of direction or significance of effect is provided. Some studies might have characterized multiple health effects or species and therefore could be represented multiple times. Row and column grand totals represent counts of distinct references. The endpoints Behavior – exploratory activity and Behavior – locomotor activity are interlinked and sometimes measured using the same open field test. However, exploratory behavior is used for endpoints that measured a specific behavior that reflected more than simple locomotor movement. This may include specific patterns of movement or other designations of exploration given by study authors.

Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-RR-16) (NTP, 2019b).

As with primary effects, Drosophila were used in a number of secondary effects studies (n = 28) to evaluate different mechanistic aspects of paraquat, including modification effects of different genes known to play a role in human familial and sporadic Parkinson’s disease (e.g., DJ-1 [parkin] and LRKK2 [leucine-rich repeat kinase 2]). Most of these studies evaluated dopamine levels or some other measure to address changes in dopamine (e.g., dopamine metabolites, density of TH immunoreactivity) (Figure F-5).

#### In Vitro Studies

Two hundred and forty-four studies were identified to have in vitro data potentially relevant to mechanistic links between paraquat exposure and Parkinson’s disease either specifically or to the nervous system in general (Figure 1); 68 of these studies only used paraquat as a positive control to induce oxidative stress and are not further characterized in this report. The most-studied outcome categories included oxidative stress, cell viability, mitochondrial effects, and changes in gene expression, which are the same categories that were most reported in the animal in vivo secondary effects (Figure 7). These most-studied categories are also general effects, whereas the endpoints that might provide more specific mechanistic information for Parkinson’s disease (e.g., TH+ neurons/dopamine and metabolite levels, α-synuclein) were less studied with a total of 16 studies each of dopaminergic neuron counts (TH+ neurons) and protein aggregation (mainly α-synuclein). The vast majority of human in vitro studies reported use of tumor cell lines including mostly SH-SY5Y, a neuroblastoma cell line originally derived from a bone marrow metastasis (48 of 80 total human in vitro studies), and the parent line of SH-SY5Y, SK-N-SH (seven studies). Only one study used primary human brain cells (HA1800 astrocytes), whereas three used Parkinson’s disease patient-derived primary fibroblasts. Similarly, very few human in vitro studies used stem cells, including neural progenitor cells (n = 6), iPSC astrocytes (n = 1), and transformed neuroblasts (n = 1). The number of studies reporting rat in vitro models were second to human models with a total of 74 studies using a variety of rat models, including the tumor cell line PC12 (n = 20), a cell line isolated from an adrenal gland tumor of embryonic origin composed partially of neuroblasts that can be differentiated into neurons with some dopaminergic characteristics (Malagelada and Greene 2008). PC12 cells were most often used to study general categories, such as oxidative stress and cell viability. Other commonly reported in vitro models derived from rat or mouse included mesencephalic models, such as the transformed rat cell line N27 (n = 17), and primary cultures of neurons and mixed cell types. Other rodent in vitro models included ex vivo studies of brain tissue cultures and brain slices, and subcellular fractionations of organelles, such as brain mitochondria and synaptosomes.

Figure 7

Number of Studies That Evaluated In Vitro Effects Evaluated Following Paraquat Exposures

Numbers indicate the counts of studies that have investigated the identified endpoints; no indication of direction or significance of effect is provided. Some studies might have characterized multiple health effects or species and therefore could be represented multiple times. Row and column grand totals represent counts of distinct references. The “Rat × Mouse” column includes studies using either a hybrid cell line or a combination of rat and mouse cells.

Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-RR-16) (NTP, 2019b).