# Methods

The systematic review techniques applied in this scoping review adhered to the framework developed by the National Toxicology Program (NTP) Office of Health Assessment and Translation (OHAT) (Rooney et al. 2014). The OHAT systematic review and evidence integration framework consists of a seven-step process in which the first three steps are relevant to producing a scoping review, and the last four steps are applicable to assessing study quality and synthesizing evidence (NTP 2015). Therefore, this scoping review was restricted to the first three steps: (1) problem formulation, (2) literature search and study selection, and (3) abbreviated data extraction. Data extraction was primarily used to capture study characteristics of all included studies; quantitative results of epidemiological and experimental mammalian studies of high external validity to human exposure (e.g., oral, inhalation, or dermal) were also extracted as reported by study authors. Qualitative evidence synthesis was limited to grouping studies according to similar study characteristics, including experimental models and exposure categories (e.g., exposed populations in epidemiological studies, exposure routes in animal studies, and in vitro model systems). Study quality assessment was beyond the aims of this evaluation, as is customary for most scoping reviews, and thus was not performed for this review.

## Problem Formulation

Parkinson’s disease was first chosen by NTP as a disease-focused scoping project due to high prevalence of cases of unknown etiology, questions about environmental exposures, and potential to inform future testing efforts. While performing scoping activities, NTP identified the association between paraquat exposure and Parkinson’s disease as a potential candidate for further review. In addition, NTP was made aware that EPA OPP and a research group from the University Estadual Paulista, São Paulo, Brazil, were also initiating systematic reviews on the same topic. Thus, to support a consistent process, promote access and data sharing, and avoid duplication of effort, NTP consulted with the research group from Brazil at the project’s initiation and collaborated closely with EPA OPP throughout scoping activities. NTP, in collaboration with EPA OPP toxicologists and epidemiologists and an expert on neurotoxicity from the EPA Office of Research and Development (ORD), defined the outcomes of interest and the inclusion/exclusion criteria for the title-and-abstract screen and full-text review. A scoping review protocol was developed using the OHAT systematic review framework for the literature screen and review and for data extraction ([underlined: Appendix G]).

## PECO Statement

A PECO ([underlined: P]opulation, [underlined: E]xposure, [underlined: C]omparator, and [underlined: O]utcome) statement was developed in conjunction with EPA to address and understand the potential effects of paraquat on neurological outcomes associated with Parkinson’s disease or parkinsonism in humans, animals, and in vitro model systems (Table 1). The PECO statement is used to help develop the specific research questions, search terms, and inclusion/exclusion criteria for the systematic review (Higgins and Green 2011).

Table 1 Population, Exposure, Comparator, Outcome Statement

PECO Element | Evidence
[underlined: P]opulations | Human: Humans, without restriction on age, sex, or life stage at exposure or outcome assessment Animal: Experimental animals without restriction on species (including nonmammalian and invertebrate species), age, sex, or life stage at exposure or outcome assessment In vitro: Human or animal cells, tissues, or model systems with in vitro exposure regimens; examples of cell lines typically used for in vitro Parkinson’s disease mechanistic study include SK-N-SH, SH-SY5Y, PC12, RBE, astrocytes, and dopaminergic neurons
[underlined: E]xposure | Exposure to paraquat dichloride (CASRN 1910-42-5) based on administered dose or concentration, biomonitoring data (e.g., urine, blood, or other specimens), environmental measures (e.g., air, water levels), or indirect measures such as job title or occupational history
[underlined: C]omparators | Human: A comparison population exposed to lower levels (or no exposure/exposure below detection levels) of paraquat Animal: Comparable animal populations that were untreated or exposed to vehicle-only treatment in experimental animal studies In vitro: Comparable cells or tissues exposed to vehicle-only treatment or untreated controls
[underlined: O]utcomes | Human: Primary outcomes: Diagnosis of Parkinson’s disease and/or clinical observations, neurobehavioral, or neuropathological outcomes typically associated with Parkinson’s disease or parkinsonism following in vivo exposure, focusing on tissue level and functional abnormalities, descriptive and/or functional assessment of the central nervous system, including the nigrostriatal (dopamine) system; examples of relevant outcomes include tremor, bradykinesia, rigidity, postural instability, and any other movement abnormalities associated with parkinsonism Secondary outcomes: Tissue, cellular, biochemical, and/or molecular outcomes resulting from in vivo exposure that have a mechanistic association with Parkinson’s disease or are evidence of toxicity in the nervous system, but are not specific to Parkinson’s disease Animal: Primary outcomes: Neurobehavioral or neuropathological outcomes, focusing on whole body and tissue level abnormalities typically associated with Parkinson’s disease following in vivo exposure; endpoints include motor activity and coordination, sensorimotor reflexes, effects on cognitive function, quantitative or qualitative assessment of dopaminergic neuron counts in the substantia nigra and dopaminergic neuron terminals in the striatum, and other descriptive and/or functional assessments of the central nervous system, including the nigrostriatal (dopamine) system, which are considered hallmarks of Parkinson’s disease (e.g., detection of intracytoplasmic Lewy bodies) Secondary outcomes: Tissue, cellular, biochemical, and/or molecular outcomes resulting from in vivo exposure that have a mechanistic association with Parkinson’s disease (e.g., dopamine and metabolite levels in the nigrostriatal pathway, tyrosine hydroxylase-positive neuron [TH+] immunoreactivity or density) or are evidence of toxicity in the nervous system, but are not specific to Parkinson’s disease (e.g., oxidative stress, inflammation, mitochondrial, and/or proteasomal dysfunction) In vitro: In vitro assays investigating cellular responses commonly attributed to Parkinson’s disease (e.g., assessment of functionality, integrity, and viability for nerve cells critical to the nigrostriatal [dopamine] system) and mechanistic assays investigating proposed pathways for the etiology of Parkinson’s disease (e.g., enzyme interactions, cell signaling)

### Primary and Secondary Outcomes

The publications selected during the paraquat literature screen included studies that examined primary and secondary outcomes related to Parkinson’s disease. Both primary and secondary outcomes were used to evaluate the connection between pesticide exposure and the disease. Primary outcomes directly associate pesticide exposure with the manifestation of Parkinson’s disease (or symptoms of neurological disruption commonly attributed to parkinsonism), whereas secondary outcomes elucidate mechanistic connections between exposure and Parkinson’s disease or describe general toxicity in the nervous system. Secondary outcomes are considered with the corresponding primary health effects to examine support for biological plausibility of those outcomes, or support for the analysis of a causal relationship (or lack thereof), between paraquat exposure and Parkinson’s disease. In humans, primary outcomes include abnormal neurobehavioral clinical observations, clinical diagnoses consistent with parkinsonism, and neuropathological aberrations. Animal primary outcomes include abnormal neurobehavioral clinical observations, neuropathological aberrations, including degeneration of dopaminergic neurons in the substantia nigra, and changes in locomotor activity. Secondary outcomes in human and animal studies cover other tissue, cellular, biochemical, or molecular changes in the nervous system that either have a mechanistic association with Parkinson’s disease or reflect general toxicity in the nervous system that is not specific to Parkinson’s disease. Indirect measures of a primary outcome (e.g., evaluating dopaminergic neuron health based on TH+ optical density) were grouped into this category because they provided supportive rather than direct evidence of the primary outcome. In vitro studies also contribute mechanistic information and can be used to assess the biological plausibility of outcomes observed in human and animal studies. Relevant in vitro outcomes include loss of nerve cell integrity and viability or altered functionality of nerve cells critical to the nigrostriatal system, and physiological changes attributed to paraquat exposure that are hypothesized to play a role in the etiology of Parkinson’s disease but are not unique consequences of the disease (e.g. oxidative stress, proteasomal and mitochondrial dysfunction in nervous tissues, and epigenetic changes). No distinction was made between primary and secondary outcomes for in vitro studies because all in vitro data were considered supporting information for the other evidence streams.

## Literature Search

### Literature Search Strategy

Database search strategies were developed to identify all relevant published evidence that addresses the relationship between Parkinson’s disease and paraquat exposure. To ensure inclusion of all relevant papers, the strategy for this search was broad for the consideration of neurobehavioral and neuropathological endpoints associated with Parkinson’s disease and comprehensive for paraquat dichloride as an exposure or treatment. All searches included terms associated with paraquat including: (1) the common name of the chemical, (2) the Chemical Abstract Services Registry Number (CASRN), and (3) retrieval of synonyms from the ChemIDplus database, which currently contains chemical names and synonyms for more than 400,000 chemicals (NIH 2018). Keywords specific to Parkinson’s disease were derived from review articles on proposed mechanistic pathways for the etiology of Parkinson’s disease (Baltazar et al. 2014; Zhang et al. 2016) and through a systematic review that investigated the relationship between chemical exposure and Parkinson’s disease (Choi et al. 2016). Searches were not limited by study design, language restrictions, or publication year. The following databases were searched most recently on May 24, 2018 (full details of the search strategies are presented in Appendix A):

- Embase (Elsevier)
- PubMed (NLM)
- Scopus (Elsevier)
- Web of Science (Thomson Reuters)
- TOXLINE

### Searching Other Resources

The reference lists of all relevant published reviews identified during the initial search were hand searched to find studies that were not identified through the electronic searches. These studies were evaluated using the same inclusion and exclusion criteria used for screening the electronic search results. Relevant studies identified through these steps are marked as “identified through other sources” in the study selection flow diagram (Figure 1).

Figure 1

Study Selection Diagram

*Several included articles contain data for multiple evidence streams.

## Study Selection

### Evidence Selection Criteria

Inclusion/exclusion criteria were designed to identify relevant publications that comply with each aspect of the PECO statement (Table 1). The eligibility of each citation from the paraquat literature was considered using the criteria outlined in Appendix B.

### Screening Process

Search results from each database were compiled in EndNote and duplicates were removed. The master reference list of original search results was filtered and sorted with the Document Classification and Topic Extraction Resource software (DoCTER), a machine-learning tool developed by ICF, to group the citations into clusters based on perceived relevance to the key questions and similarity to vetted studies. Clusters were used to prioritize manual screening in order of highest-to-lowest perceived relevance. The references in each cluster were then screened at each stage as described below for relevance and eligibility with the inclusion/exclusion criteria used by the online literature screening program, DistillerSR^®^, a web-based, systematic review software program with structured forms and procedures (http://systematic-review.net/).

#### Title-and-abstract Review

Screeners were trained using the detailed inclusion/exclusion criteria outlined in Appendix B with an initial pilot screening phase of a minimum of 150 references (actual n = 172) to improve clarity of the inclusion and exclusion instructions and to improve accuracy and consistency among screeners. Changes to the inclusion criteria resulting from the pilot phase were documented in a protocol amendment along with the date of modifications and the logic for the changes. After the pilot phase, trained screeners used updated inclusion/exclusion criteria to conduct a title-and-abstract screen of each reference in duplicate to determine study eligibility. If considered possibly relevant, studies were moved to a full-text review. In the case of screening conflicts, screeners independently reviewed their screening results to confirm the inclusion/exclusion decision and, if needed, discussed discrepancies with the other screeners. If a true disagreement existed between screeners, the study passed to the full-text review.

#### Full-Text Review

After completion of the title-and-abstract screen, full-text articles were retrieved for those studies that either clearly met the inclusion criteria or for which eligibility to meet the inclusion criteria was unclear. Two screeners who participated in the title-and-abstract screening independently conducted the full-text review. True disagreements were resolved by discussion through consultation with other members of the evaluation design team and technical advisors.

Reason for exclusion at the full-text-review stage was annotated and is reported in a study selection flow diagram using reporting practices outlined in Moher et al. (2009) (Figure 1). Although more than one reason might have applied, only one of the following reasons for exclusion was documented for simplicity: (1) lacked a comparator (e.g., a control or baseline group); (2) conducted with a nonanimal model (e.g., plants, fungi, protists, or bacteria); (3) lacked neurobehavioral or neuropathological health outcome information; (4) conducted on wildlife; (5) lacked paraquat exposure; (6) mixture study lacked paraquat-only exposure; (7) was a conference abstract, grant application/registration, thesis/dissertation, or otherwise not a peer-reviewed scientific publication; or (8) study was only available in non-English language.

##### Multiple Publications of Same Data

During full-text review, publications were examined for overlapping data by comparing author affiliations, study designs, cohort names, enrollment criteria, and enrollment dates. No publications with overlapping data were identified in this review.

## Data Extraction

Data were extracted from the full-text records of individual studies by one member of the scoping review team and checked by a second member for completeness and accuracy. Any discrepancies in data extraction were resolved by discussion or consultation with a third member of the team.

Two levels of data extraction were performed during scoping activities depending on study type and design: abbreviated data extraction of study characteristics of all included studies to capture study characteristics including species tested, routes and levels of exposure, and endpoints measured; and full data extraction including quantitative health effects data from epidemiological studies and experimental animal studies of high external validity to human exposures reporting primary outcomes.

Secondary outcomes reported in experimental mammalian animal studies and all outcomes reported in nonmammalian animal and in vitro models were included only as supporting information because the measured effects were less specific to Parkinson’s disease than those measured for primary outcome studies in mammals. Instead, only abbreviated data extraction was performed on these studies. These characteristics were identified in the full-text record and coded into Microsoft Excel spreadsheets to facilitate data visualization and summary using Tableau^®^ software.

Full data extractions of included epidemiology studies and experimental studies of mammals exposed to paraquat via oral, dermal, or inhalation exposure routes, both reporting primary outcomes, were conducted using the Health Assessment Workspace Collaborative (HAWC) (https://hawc.readthedocs.io/en/latest/), a free and open-source, web-based software application. Partial data extraction for other studies was performed using Microsoft Excel. Full data extraction included information on author affiliations and funding, characteristics of the model organism, exposure methodology and conditions, the route of administration, comparators, and quantitative and qualitative data on health effects. Data extraction elements collected from epidemiological studies are listed in Appendix C and those from animal studies in Appendix D.

### Data Availability

Interactive versions of each figure can be accessed directly using the link included beneath each figure. In addition, all interactive figures and additional study details can be viewed online and data can be downloaded from [underlined: Tableau] in Microsoft Excel format here: https://doi.org/10.22427/NTP-DATA-RR-16 (NTP, 2019b). Full data extraction results are available for download from HAWC in Microsoft Excel format here: https://hawcproject.org/assessment/475/ (NTP, 2019a).