# Introduction

Parkinson’s disease is a group of motor system disorders that are due to progressive degeneration of dopaminergic neurons within the substantia nigra of the brain. Although some genetic factors are known to contribute to familial Parkinson’s disease, the cause of most cases remains unknown. Increasingly, the potential contributions of environmental factors—including exposures to pesticides, metals, and other environmental chemicals—have been investigated in observational human, experimental animal, and in vitro studies. Meta-analyses of epidemiological data have identified elevated risks of Parkinson’s disease in farmworkers and others who handle pesticides or live near areas close to pesticide use or production (Ahmed et al. 2017).

Paraquat dichloride (1,1'-dimethyl-4,4'-bipyridinium ion, hereafter referred to as paraquat) is a quaternary ammonium compound used as a broad-spectrum, fast-acting contact herbicide. Paraquat is registered for use in both agricultural and nonagricultural settings, and is used to control weeds and as a post-harvest desiccant (Bromilow 2004). It is applied as a direct spray and kills the leaves that come in direct contact with the compound.

Importantly, paraquat is a restricted-use pesticide (i.e., it can only be purchased and used by people certified to apply pesticides) and is not registered for any homeowner or residential applications in the United States. Thus, the primary route of exposure for paraquat is occupational exposure during mixing, loading, and applying paraquat or during post-application processes. However, residential exposure can occur for those living on or near farms where paraquat has been applied. Normal use patterns suggest that paraquat is not expected to be a surface water or groundwater contaminant (US EPA 1997). Whereas high-level, acute exposure to paraquat is associated with pulmonary toxicity in humans and experimental animals, low-level, chronic exposure is reported to be associated with various health effects, including central nervous system toxicity, which can lead to Parkinson’s disease (Dinis-Oliveira et al. 2008).

The association between paraquat exposure and Parkinson’s disease was identified as a potential candidate for systematic review as a result of a National Toxicology Program (NTP) scoping activity of Parkinson’s disease (https://ntp.niehs.nih.gov/go/parkinson). The same topic was also identified as a topic for systematic review by two external groups. The U.S. Environmental Protection Agency (EPA) Office of Pesticide Programs (OPP) is evaluating paraquat as part of its pesticide registration review program and collaborated closely with NTP during the scoping process. A second academic group from Brazil also contacted NTP for advice on the planning and conduct of its separate, independent systematic review of paraquat and Parkinson’s disease (Vaccari et al. 2019). Because of the interest and extent of the evidence, NTP conducted this targeted scoping review of the literature on paraquat exposure and Parkinson’s disease. The literature was systematically collected and categorized to develop an interactive evidence map to enable researchers to explore the data by key Parkinson’s disease-related health effects, types of evidence, and gaps in research. The information contained in this scoping report can be used to focus and support a full systematic review by any interested group or for consideration of future research on this topic.

## Objective and Specific Aims

### Objective

The primary objective of this scoping review was to identify and characterize the literature relevant to paraquat exposure and neurobehavioral or neuropathological endpoints associated with Parkinson’s disease in humans and to related models in experimental animal or in vitro studies.

### Specific Aims

- Identify literature reporting the effects of paraquat exposure on neurobehavioral and neuropathological endpoints associated with Parkinson’s disease or clinical symptoms of parkinsonism (i.e., tremors of the extremities, slowed movement, postural rigidity, and changes in gait) in humans, animals, and in vitro model systems.
- Extract study design information from included studies, such as evidence stream, exposure scheme, and measured effects. Data extraction files of the included studies will be shared upon release of the final report.
- Summarize the available literature and create an evidence map of the health effects and mechanistic data relevant to Parkinson’s disease (i.e., the extent and types of health effects evidence available) associated with paraquat exposure.