# Appendix F Supplemental Figures

Figure F-1

Number of Epidemiological Studies of Parkinson's Disease-related Outcomes Following Paraquat Exposure

Some studies might have characterized multiple populations or used multiple study designs and therefore could be listed multiple times. Row and column totals and grand total shown in the figure represent counts of distinct references.

Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-RR-16) (NTP, 2019b).

Created using Tableau.

Figure F-2

Occupational Paraquat Exposure and Parkinsonism Outcomes

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/475/) (NTP, 2019a).

Created using HAWC.

Tomenson and Campbell (2011) is not included in this visualization because study results are provided as standardized mortality ratios and not odds ratios.

Kamel et al. (2007) is classified here as a prospective cohort study but includes a prospective analysis (incidence) and cross-sectional analysis (prevalence).

Pouchieu et al. (2018) is classified here as a cross-sectional analysis. The study evaluates the AGRICAN cohort, but results were from the baseline questionnaire only.

Figure F-3

Environmental Paraquat Exposure and Parkinsonism Outcomes

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/475/) (NTP, 2019a).

Created using HAWC.

For Lee et al. (2012), the result is significant, but authors did not provide a p value.

Figure F-4

General Population Paraquat Exposure and Parkinsonism Outcomes

Interactive figure and additional study details in HAWC (https://hawcproject.org/assessment/475/) (NTP, 2019a).

Created using HAWC.

Hertzman et al. (1990) is not included in this visualization. Hertzman et al. reported that odds ratios could not be calculated because four Parkinson’s disease patients and no controls reported paraquat contact.

Wan and Lin (2016) is also not included in this visualization because it is an ecological spatial analysis with results not comparable with results from other studies.

Figure F-5

Number of Studies that Evaluated Secondary Animal Effects Following Paraquat Exposures in Nonmammalian Models

Some studies might have characterized multiple health effects or species and therefore could be listed multiple times. Row and column totals and grand total shown in the figure represent counts of distinct references.

Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-RR-16) (NTP, 2019b).

Created using Tableau.