# Appendix E List of Included Studies

## E.1 Human Studies: Primary Endpoints

Certain studies in this list are also included in the Animal Studies: Secondary Endpoints list and in the In Vitro Studies list if they contained data relating to those endpoints in addition to human primary endpoints.

Brouwer M, Huss A, van der Mark M, Nijssen PCG, Mulleners WM, Sas AMG, van Laar T, de Snoo GR, Kromhout H, Vermeulen RCH. 2017. Environmental exposure to pesticides and the risk of Parkinson's disease in the Netherlands. Environ Int. 107:100-110. https://doi.org/10.1016/j.envint.2017.07.001

Costello S, Cockburn M, Bronstein J, Zhang X, Ritz B. 2009. Parkinson's disease and residential exposure to maneb and paraquat from agricultural applications in the central valley of California. Am J Epidemiol. 169(8):919-926. https://doi.org/10.1093/aje/kwp006

Dhillon AS, Tarbutton GL, Levin JL, Plotkin GM, Lowry LK, Nalbone JT, Shepherd S. 2008. Pesticide/environmental exposures and Parkinson's disease in East Texas. J Agromed. 13(1):37-48. https://doi.org/10.1080/10599240801986215

Engel L, Checkoway H, Keifer M, Seixas N, Longstreth W, Scott K, Hudnell K, Anger W, Camicioli R. 2001. Parkinsonism and occupational exposure to pesticides. Occup Environ Med. 58(9):582-589.

Firestone JA, Lundin JI, Powers KM, Smith‐Weller T, Franklin GM, Swanson PD, Longstreth Jr W, Checkoway H. 2010. Occupational factors and risk of Parkinson's disease: A population‐based case-control study. Am J Ind Med. 53(3):217-223.

Firestone JA, Smith-Weller T, Franklin G, Swanson P, Longstreth WT, Jr., Checkoway H. 2005. Pesticides and risk of Parkinson disease: A population-based case-control study. Arch Neurol. 62(1):91-95. https://doi.org/10.1001/archneur.62.1.91

Furlong M, Tanner CM, Goldman SM, Bhudhikanok GS, Blair A, Chade A, Comyns K, Hoppin JA, Kasten M, Korell M et al. 2015. Protective glove use and hygiene habits modify the associations of specific pesticides with Parkinson's disease. Environ Int. 75:144-150. https://doi.org/10.1016/j.envint.2014.11.002

Gatto NM, Cockburn M, Bronstein J, Manthripragada AD, Ritz B. 2009. Well-water consumption and Parkinson's disease in rural California. Environ Health Perspect. 117(12):1912-1918. https://doi.org/10.1289/ehp.0900852

Gatto NM, Rhodes SL, Manthripragada AD, Bronstein J, Cockburn M, Farrer M, Ritz B. 2010. alpha-Synuclein gene may interact with environmental factors in increasing risk of Parkinson's disease. Neuroepidemiology. 35(3):191-195. https://doi.org/10.1159/000315157

Goldman SM, Kamel F, Ross GW, Bhudhikanok GS, Hoppin JA, Korell M, Marras C, Meng C, Umbach DM, Kasten M et al. 2012. Genetic modification of the association of paraquat and Parkinson's disease. Mov Disord. 27(13):1652-1658. https://doi.org/10.1002/mds.25216

Hertzman C, Wiens M, Bowering D, Snow B, Calne D. 1990. Parkinson's disease: A case-control study of occupational and environmental risk factors. Am J Ind Med. 17(3):349-355.

Hertzman C, Wiens M, Snow B, Kelly S, Calne D. 1994. A case‐control study of Parkinson's disease in a horticultural region of British Columbia. Mov Disord. 9(1):69-75.

Kamel F, Goldman SM, Umbach DM, Chen H, Richardson G, Barber MR, Meng C, Marras C, Korell M, Kasten M et al. 2014. Dietary fat intake, pesticide use, and Parkinson's disease. Parkinsonism Relat Disord. 20(1):82-87. https://doi.org/10.1016/j.parkreldis.2013.09.023

Kamel F, Tanner CM, Umbach DM, Hoppin JA, Alavanja MCR, Blair A, Comyns K, Goldman SM, Korell M, Langston JW et al. 2007. Pesticide exposure and self-reported Parkinson's disease in the agricultural health study. Am J Epidemiol. 165(4):364-374. https://doi.org/10.1093/aje/kwk024

Lee PC, Bordelon Y, Bronstein J, Ritz B. 2012. Traumatic brain injury, paraquat exposure, and their relationship to Parkinson disease. Neurology. 79(20):2061-2066. https://doi.org/10.1212/WNL.0b013e3182749f28

Liou HH, Tsai MC, Chen CJ, Jeng JS, Chang YC, Chen SY, Chen RC. 1997. Environmental risk factors and Parkinson's disease: A case-control study in Taiwan. Neurology. 48(6):1583-1588. https://doi.org/10.1212/wnl.48.6.1583

Pouchieu C, Piel C, Carles C, Gruber A, Helmer C, Tual S, Marcotullio E, Lebailly P, Baldi I. 2018. Pesticide use in agriculture and Parkinson's disease in the AGRICAN cohort study. Int J Epidemiol. 47(1):299-310. https://doi.org/10.1093/ije/dyx225

Sanders LH, Paul KC, Howlett EH, Lawal H, Boppana S, Bronstein JM, Ritz B, Greenamyre JT. 2017. Editor's highlight: Base excision repair variants and pesticide exposure increase Parkinson's disease risk. Toxicol Sci. 158(1):188-198. https://doi.org/10.1093/toxsci/kfx086

Tanner CM, Kamel F, Ross GW, Hoppin JA, Goldman SM, Korell M, Marras C, Bhudhikanok GS, Kasten M, Chade AR et al. 2011. Rotenone, paraquat, and Parkinson's disease. Environ Health Perspect. 119(6):866-872. https://doi.org/10.1289/ehp.1002839

Tanner CM, Ross GW, Jewell SA, Hauser RA, Jankovic J, Factor SA, Bressman S, Deligtisch A, Marras C, Lyons KE et al. 2009. Occupation and risk of parkinsonism a multicenter case-control study. Arch Neurol. 66(9):1106-1113.

Tomenson JA, Campbell C. 2011. Mortality from Parkinson's disease and other causes among a workforce manufacturing paraquat: A retrospective cohort study. BMJ open. 1(2):e000283. https://doi.org/10.1136/bmjopen-2011-000283

van der Mark M, Vermeulen R, Nijssen PC, Mulleners WM, Sas AM, Van Laar T, Brouwer M, Huss A, Kromhout H. 2014. Occupational exposure to pesticides and endotoxin and Parkinson disease in the Netherlands. Occup Environ Med. 71(11):757-764.

Wan N, Lin G. 2016. Parkinson's disease and pesticides exposure: New findings from a comprehensive study in Nebraska, USA. J Rural Health. 32(3):303-313. https://doi.org/10.1111/jrh.12154

Wang A, Costello S, Cockburn M, Zhang X, Bronstein J, Ritz B. 2011. Parkinson's disease risk from ambient exposure to pesticides. Eur J Epidemiol. 26(7):547-555. https://doi.org/10.1007/s10654-011-9574-5

## E.2 Human Studies: Secondary Endpoints

Ranjbar A, Pasalar P, Sedighi A, Abdollahi M. 2002. Induction of oxidative stress in paraquat formulating workers. Toxicol Lett. 131(3):191-194.

## E.3 Animal Studies: Primary Endpoints

Certain studies in this list are also included in the Animal Studies: Secondary Endpoints list and in the In Vitro Studies list if they contained data relating to those endpoints in addition to animal primary endpoints.

Ait-Bali Y, Ba-M'hamed S, Bennis M. 2016. Prenatal paraquat exposure induces neurobehavioral and cognitive changes in mice offspring. Environ Toxicol Pharmacol. 48:53-62. https://doi.org/10.1016/j.etap.2016.10.008

Anselmi L, Toti L, Bove C, Hampton J, Travagli RA. 2017. A nigro-vagal pathway controls gastric motility and is affected in a rat model of Parkinsonism. Gastroenterology. 153(6):1581-1593. https://doi.org/10.1053/j.gastro.2017.08.069

Attia HN, Maklad YA. 2018. Neuroprotective effects of coenzyme Q10 on paraquat-induced Parkinson's disease in experimental animals. Behav Pharmacol. 29(1):79-86. https://doi.org/10.1097/fbp.0000000000000342

Bagetta G, Corasaniti MT, Iannone M, Nistico G, Stephenson JD. 1992. Production of limbic motor seizures and brain damage by systemic and intracerebral injections of paraquat in rats. Pharmacol Toxicol. 71(6):443-448.

Bajo-Graneras R, Ganfornina MD, Martin-Tejedor E, Sanchez D. 2011. Apolipoprotein D mediates autocrine protection of astrocytes and controls their reactivity level, contributing to the functional maintenance of paraquat-challenged dopaminergic systems. Glia. 59(10):1551-1566. https://doi.org/10.1002/glia.21200

Barbeau A, Dallaire L, Buu NT, Poirier J, Rucinska E. 1985. Comparative behavioral, biochemical and pigmentary effects of MPTP, MPP+ and paraquat in Rana pipiens. Life Sci. 37(16):1529-1538. https://doi.org/10.1016/0024-3205(85)90185-7

Barlow BK, Richfield EK, Cory-Slechta DA, Thiruchelvam M. 2004. A fetal risk factor for Parkinson's disease. Dev Neurosci. 26(1):11-23. https://doi.org/10.1159/000080707

Bingol B, Tea JS, Phu L, Reichelt M, Bakalarski CE, Song Q, Foreman O, Kirkpatrick DS, Sheng M. 2014. The mitochondrial deubiquitinase USP30 opposes parkin-mediated mitophagy. Nature. 510(7505):370-375. https://doi.org/10.1038/nature13418

Bobyn J, Mangano EN, Gandhi A, Nelson E, Moloney K, Clarke M, Hayley S. 2012. Viral-toxin interactions and Parkinson's disease: poly I:C priming enhanced the neurodegenerative effects of paraquat. J Neuroinflammation. 9:86. https://doi.org/10.1186/1742-2094-9-86

Bortolotto JW, Cognato GP, Christoff RR, Roesler LN, Leite CE, Kist LW, Bogo MR, Vianna MR, Bonan CD. 2014. Long-term exposure to paraquat alters behavioral parameters and dopamine levels in adult zebrafish (Danio rerio). Zebrafish. 11(2):142-153. https://doi.org/10.1089/zeb.2013.0923

Breckenridge CB, Sturgess NC, Butt M, Wolf JC, Zadory D, Beck M, Mathews JM, Tisdel MO, Minnema D, Travis KZ et al. 2013. Pharmacokinetic, neurochemical, stereological and neuropathological studies on the potential effects of paraquat in the substantia nigra pars compacta and striatum of male C57BL/6J mice. Neurotoxicology. 37:1-14. https://doi.org/10.1016/j.neuro.2013.03.005

Bretaud S, Lee S, Guo S. 2004. Sensitivity of zebrafish to environmental toxins implicated in Parkinson's disease. Neurotoxicol Teratol. 26(6):857-864. https://doi.org/10.1016/j.ntt.2004.06.014

Brooks AI, Chadwick CA, Gelbard HA, Cory-Slechta DA, Federoff HJ. 1999. Paraquat elicited neurobehavioral syndrome caused by dopaminergic neuron loss. Brain Res. 823(1-2):1-10. https://doi.org/10.1016/s0006-8993(98)01192-5

Calo M, Iannone M, Passafaro M, Nistico G. 1990. Selective vulnerability of hippocampal CA3 neurones after microinfusion of paraquat into the rat substantia nigra or into the ventral tegmental area. J Comp Pathol. 103(1):73-78. https://doi.org/10.1016/s0021-9975(08)80136-3

Campos FL, Carvalho MM, Cristovao AC, Je G, Baltazar G, Salgado AJ, Kim YS, Sousa N. 2013. Rodent models of Parkinson's disease: Beyond the motor symptomatology. Front Behav Neurosci. 7:175. https://doi.org/10.3389/fnbeh.2013.00175

Caroleo MC, Rispoli V, Arbitrio M, Strongoli C, Rainaldi G, Rotiroti D, Nistico G. 1996. Chronic administration of paraquat produces immunosuppression of T lymphocytes and astrocytosis in rats. Toxic Subst Mech. 15(3):183-194.

Chanyachukul T, Yoovathaworn K, Thongsaard W, Chongthammakun S, Navasumrit P, Satayavivad J. 2004. Attenuation of paraquat-induced motor behavior and neurochemical disturbances by L-valine in vivo. Toxicol Lett. 150(3):259-269. https://doi.org/10.1016/j.toxlet.2004.02.007

Chaudhuri A, Bowling K, Funderburk C, Lawal H, Inamdar A, Wang Z, O'Donnell JM. 2007. Interaction of genetic and environmental factors in a Drosophila parkinsonism model. J Neurosci. 27(10):2457-2467. https://doi.org/10.1523/jneurosci.4239-06.2007

Chen AY, Tully T. 2018. A stress-enhanced model for discovery of disease-modifying gene: Ece1-suppresses the toxicity of alpha-synuclein A30P. Neurobiol Dis. 114:153-163. https://doi.org/10.1016/j.nbd.2018.03.003

Chen LJ, Yoo SE, Na R, Liu YH, Ran QT. 2012. Cognitive impairment and increased A beta levels induced by paraquat exposure are attenuated by enhanced removal of mitochondrial H2O2. Neurobiol Aging. 33(2). https://doi.org/10.1016/j.neurobiolaging.2011.01.008

Chen P, Chen Z, Li A, Lou XC, Wu XK, Zhao CJ, Wang SL, Liang LP. 2008. Catalytic metalloporphyrin protects against paraquat neurotoxicity in vivo. Biomed Environ Sci. 21(3):233-238. https://doi.org/10.1016/s0895-3988(08)60035-5

Chen Q, Niu Y, Zhang R, Guo H, Gao Y, Li Y, Liu R. 2010. The toxic influence of paraquat on hippocampus of mice: Involvement of oxidative stress. Neurotoxicology. 31(3):310-316. https://doi.org/10.1016/j.neuro.2010.02.006

Chinta SJ, Woods G, Demaria M, Rane A, Zou Y, McQuade A, Rajagopalan S, Limbad C, Madden DT, Campisi J et al. 2018. Cellular senescence is induced by the environmental neurotoxin paraquat and contributes to neuropathology linked to Parkinson's disease. Cell Rep. 22(4):930-940. https://doi.org/10.1016/j.celrep.2017.12.092

Choi HS, An JJ, Kim SY, Lee SH, Kim DW, Yoo KY, Won MH, Kang TC, Kwon HJ, Kang JH et al. 2006. PEP-1-SOD fusion protein efficiently protects against paraquat-induced dopaminergic neuron damage in a Parkinson disease mouse model. Free Radic Biol Med. 41(7):1058-1068. https://doi.org/10.1016/j.freeradbiomed.2006.06.006

Choi WS, Abel G, Klintworth H, Flavell RA, Xia Z. 2010. JNK3 mediates paraquat- and rotenone-induced dopaminergic neuron death. J Neuropathol Exp Neurol. 69(5):511-520. https://doi.org/10.1097/NEN.0b013e3181db8100

Cicchetti F, Lapointe N, Roberge-Tremblay A, Saint-Pierre M, Jimenez L, Ficke BW, Gross RE. 2005. Systemic exposure to paraquat and maneb models early Parkinson's disease in young adult rats. Neurobiol Dis. 20(2):360-371. https://doi.org/10.1016/j.nbd.2005.03.018

Corasaniti MT, Bagetta G, Rodino P, Gratteri S, Nistico G. 1992. Neurotoxic effects induced by intracerebral and systemic injection of paraquat in rats. Hum Exp Toxicol. 11(6):535-539. https://doi.org/10.1177/096032719201100616

Costa KM, Maciel IS, Kist LW, Campos MM, Bogo MR. 2014. Pharmacological inhibition of CXCR2 chemokine receptors modulates paraquat-induced intoxication in rats. PLoS One. 9(8):e105740. https://doi.org/10.1371/journal.pone.0105740

Coughlan C, Walker DI, Lohr KM, Richardson JR, Saba LM, Caudle WM, Fritz KS, Roede JR. 2015. Comparative proteomic analysis of carbonylated proteins from the striatum and cortex of pesticide-treated mice. Parkinsons Dis. 2015:812532. https://doi.org/10.1155/2015/812532

Cristovao AC, Choi DH, Baltazar G, Beal MF, Kim YS. 2009. The role of NADPH oxidase 1-derived reactive oxygen species in paraquat-mediated dopaminergic cell death. Antioxid Redox Signal. 11(9):2105-2118. https://doi.org/10.1089/ars.2009.2459

Cristovao AC, Guhathakurta S, Bok E, Je G, Yoo SD, Choi DH, Kim YS. 2012. NADPH oxidase 1 mediates alpha-synucleinopathy in Parkinson's disease. J Neurosci. 32(42):14465-14477. https://doi.org/10.1523/jneurosci.2246-12.2012

Czerniczyniec A, Karadayian AG, Bustamante J, Cutrera RA, Lores-Arnaiz S. 2011. Paraquat induces behavioral changes and cortical and striatal mitochondrial dysfunction. Free Radic Biol Med. 51(7):1428-1436. https://doi.org/10.1016/j.freeradbiomed.2011.06.034

de Oliveira Souza A, Couto-Lima CA, Rosa Machado MC, Espreafico EM, Pinheiro Ramos RG, Alberici LC. 2017. Protective action of Omega-3 on paraquat intoxication in Drosophila melanogaster. J Toxicol Environ Health A. 80(19-21):1050-1063. https://doi.org/10.1080/15287394.2017.1357345

Degori N, Froio F, Strongoli MC, Defrancesco A, Calo M, Nistico G. 1988. Behavioural and electrocortical changes induced by paraquat after injection in specific areas of the brain of the rat. Neuropharmacology. 27(2):201-207. https://doi.org/10.1016/0028-3908(88)90171-2

Ellwanger JH, Molz P, Dallemole DR, Pereira dos Santos A, Müller TE, Cappelletti L, Goncalves da Silva M, Franke SI, Pra D, Pegas Henriques JA. 2015. Selenium reduces bradykinesia and DNA damage in a rat model of Parkinson's disease. Nutrition. 31(2):359-365. https://doi.org/10.1016/j.nut.2014.07.004

Fahim MA, Shehab S, Nemmar A, Adem A, Dhanasekaran S, Hasan MY. 2013. Daily subacute paraquat exposure decreases muscle function and substantia nigra dopamine level. Physiol Res. 62(3):313-321.

Fernagut PO, Hutson CB, Fleming SM, Tetreaut NA, Salcedo J, Masliah E, Chesselet MF. 2007. Behavioral and histopathological consequences of paraquat intoxication in mice: Effects of alpha-synuclein over-expression. Synapse. 61(12):991-1001. https://doi.org/10.1002/syn.20456

Fredriksson A, Fredriksson M, Eriksson P. 1993. Neonatal exposure to paraquat or MPTP induces permanent changes in striatum dopamine and behavior in adult mice. Toxicol Appl Pharmacol. 122(2):258-264. https://doi.org/10.1006/taap.1993.1194

Gollamudi S, Johri A, Calingasan NY, Yang L, Elemento O, Beal MF. 2012. Concordant signaling pathways produced by pesticide exposure in mice correspond to pathways identified in human Parkinson's disease. PLoS One. 7(5):e36191. https://doi.org/10.1371/journal.pone.0036191

Goncalves C, Dos Santos DB, Portilho SS, Lopes MW, Ghizoni H, de Souza V, Mack JM, Naime AA, Dafre AL, de Souza Brocardo P et al. 2018. Lipopolysaccharide-induced striatal nitrosative stress and impaired social recognition memory are not magnified by paraquat coexposure. Neurochem Res. 43(3):745-759. https://doi.org/10.1007/s11064-018-2477-z

Gourgou E, Chronis N. 2016. Chemically induced oxidative stress affects ASH neuronal function and behavior in C-elegans. Sci Rep. 6. https://doi.org/10.1038/srep38147

Hara S, Iwata N, Kuriiwa F, Kano S, Kawaguchi N, Endo T. 1993. Involvement of opioid receptors in shaking behaviour induced by paraquat in rats. Pharmacol Toxicol. 73(3):146-149.

Heredia L, Belles M, Llovet MI, Domingo JL, Linares V. 2015. Neurobehavioral effects of concurrent exposure to cesium-137 and paraquat during neonatal development in mice. Toxicology. 329:73-79. https://doi.org/10.1016/j.tox.2015.01.012

Hutson CB, Lazo CR, Mortazavi F, Giza CC, Hovda D, Chesselet MF. 2011. Traumatic brain injury in adult rats causes progressive nigrostriatal dopaminergic cell loss and enhanced vulnerability to the pesticide paraquat. J Neurotrauma. 28(9):1783-1801. https://doi.org/10.1089/neu.2010.1723

Iannone M, Calo M, Rispoli V, Sancesario G, Nistico G. 1988. Neuropathological lesions after microinfusion of paraquat and MPP+ into different areas of the rat brain. Acta Neurol (Napoli). 10(6):313-321.

Inamdar AA, Chaudhuri A, O'Donnell J. 2012. The protective effect of minocycline in a paraquat-induced Parkinson's disease model in Drosophila is modified in altered genetic backgrounds. Parkinsons Dis. 2012:938528. https://doi.org/10.1155/2012/938528

Jahromi SR, Haddadi M, Shivanandappa T, Ramesh SR. 2015. Attenuation of neuromotor deficits by natural antioxidants of Decalepis hamiltonii in transgenic Drosophila model of Parkinson's disease. Neuroscience. 293:136-150. https://doi.org/10.1016/j.neuroscience.2015.02.048

Janda E, Parafati M, Aprigliano S, Carresi C, Visalli V, Sacco I, Ventrice D, Mega T, Vadala N, Rinaldi S et al. 2013. The antidote effect of quinone oxidoreductase 2 inhibitor against paraquat-induced toxicity in vitro and in vivo. Br J Pharmacol. 168(1):46-59. https://doi.org/10.1111/j.1476-5381.2012.01870.x

Jhonsa DJ, Badgujar LB, Sutariya BK, Saraf MN. 2016. Neuroprotective effect of flavonoids against paraquat induced oxidative stress and neurotoxicity in Drosophila melanogaster. Current Topics in Nutraceutical Research. 14(4):283-294.

Jiao Y, Lu L, Williams RW, Smeyne RJ. 2012. Genetic dissection of strain dependent paraquat-induced neurodegeneration in the substantia nigra pars compacta. PLoS One. 7(1):e29447. https://doi.org/10.1371/journal.pone.0029447

Kang MJ, Gil SJ, Koh HC. 2009. Paraquat induces alternation of the dopamine catabolic pathways and glutathione levels in the substantia nigra of mice. Toxicol Lett. 188(2):148-152. https://doi.org/10.1016/j.toxlet.2009.03.026

Kang MJ, Gil SJ, Lee JE, Koh HC. 2010. Selective vulnerability of the striatal subregions of C57BL/6 mice to paraquat. Toxicol Lett. 195(2-3):127-134. https://doi.org/10.1016/j.toxlet.2010.03.011

Khwaja M, McCormack A, McIntosh JM, Di Monte DA, Quik M. 2007. Nicotine partially protects against paraquat‐induced nigrostriatal damage in mice; link to α6β2* nAChRs. J Neurochem. 100(1):180-190. https://doi.org/10.1111/j.1471-4159.2006.04177.x

Kumar A, Ahmad I, Shukla S, Singh BK, Patel DK, Pandey HP, Singh C. 2010. Effect of zinc and paraquat co-exposure on neurodegeneration: Modulation of oxidative stress and expression of metallothioneins, toxicant responsive and transporter genes in rats. Free Radic Res. 44(8):950-965. https://doi.org/10.3109/10715762.2010.492832

Kumar A, Christian PK, Panchal K, Guruprasad BR, Tiwari AK. 2017. Supplementation of spirulina (Arthrospira platensis) improves lifespan and locomotor activity in paraquat-sensitive DJ-1beta(Delta93) flies, a Parkinson's disease model in Drosophila melanogaster. J Diet Suppl. 14(5):573-588. https://doi.org/10.1080/19390211.2016.1275917

Kumar A, Singh BK, Ahmad I, Shukla S, Patel DK, Srivastava G, Kumar V, Pandey HP, Singh C. 2012. Involvement of NADPH oxidase and glutathione in zinc-induced dopaminergic neurodegeneration in rats: Similarity with paraquat neurotoxicity. Brain Res. 1438:48-64. https://doi.org/10.1016/j.brainres.2011.12.028

Kuter K, Smialowska M, Wieronska J, Zieba B, Wardas J, Pietraszek M, Nowak P, Biedka I, Roczniak W, Konieczny J et al. 2007. Toxic influence of subchronic paraquat administration on dopaminergic neurons in rats. Brain Res. 1155:196-207. https://doi.org/10.1016/j.brainres.2007.04.018

Lawal HO, Chang HY, Terrell AN, Brooks ES, Pulido D, Simon AF, Krantz DE. 2010. The Drosophila vesicular monoamine transporter reduces pesticide-induced loss of dopaminergic neurons. Neurobiol Dis. 40(1):102-112. https://doi.org/10.1016/j.nbd.2010.05.008

Li H, Wu S, Wang Z, Lin W, Zhang C, Huang B. 2012. Neuroprotective effects of tert-butylhydroquinone on paraquat-induced dopaminergic cell degeneration in C57BL/6 mice and in PC12 cells. Arch Toxicol. 86(11):1729-1740. https://doi.org/10.1007/s00204-012-0935-y

Li HF, Zhao SX, Xing BP, Sun ML. 2015. Ulinastatin suppresses endoplasmic reticulum stress and apoptosis in the hippocampus of rats with acute paraquat poisoning. Neural Regen Res. 10(3):467-472. https://doi.org/10.4103/1673-5374.153698

Li K, Cheng X, Jiang J, Wang J, Xie J, Hu X, Huang Y, Song L, Liu M, Cai L et al. 2017. The toxic influence of paraquat on hippocampal neurogenesis in adult mice. Food Chem Toxicol. 106(Pt A):356-366. https://doi.org/10.1016/j.fct.2017.05.067

Li X, Yin J, Cheng CM, Sun JL, Li Z, Wu YL. 2005. Paraquat induces selective dopaminergic nigrostriatal degeneration in aging C57BL/6 mice. Chin Med J. 118(16):1357-1361.

Liou HH, Chen RC, Chen TH, Tsai YF, Tsai MC. 2001. Attenuation of paraquat-induced dopaminergic toxicity on the substantia nigra by (-)-deprenyl in vivo. Toxicol Appl Pharmacol. 172(1):37-43. https://doi.org/10.1006/taap.2001.9130

Liou HH, Chen RC, Tsai YF, Chen WP, Chang YC, Tsai MC. 1996. Effects of paraquat on the substantia nigra of the wistar rats: Neurochemical, histological, and behavioral studies. Toxicol Appl Pharmacol. 137(1):34-41. https://doi.org/10.1006/taap.1996.0054

Litteljohn D, Mangano E, Shukla N, Hayley S. 2009. Interferon-gamma deficiency modifies the motor and co-morbid behavioral pathology and neurochemical changes provoked by the pesticide paraquat. Neuroscience. 164(4):1894-1906. https://doi.org/10.1016/j.neuroscience.2009.09.025

Litteljohn D, Mangano EN, Hayley S. 2008. Cyclooxygenase-2 deficiency modifies the neurochemical effects, motor impairment and co-morbid anxiety provoked by paraquat administration in mice. Eur J Neurosci. 28(4):707-716. https://doi.org/10.1111/j.1460-9568.2008.06371.x

Litteljohn D, Nelson E, Bethune C, Hayley S. 2011. The effects of paraquat on regional brain neurotransmitter activity, hippocampal BDNF and behavioural function in female mice. Neurosci Lett. 502(3):186-191. https://doi.org/10.1016/j.neulet.2011.07.041

Lou D, Wang Q, Huang M, Zhou Z. 2016. Does age matter? Comparison of neurobehavioral effects of paraquat exposure on postnatal and adult C57BL/6 mice. Toxicol Mech Methods. 26(9):667-673. https://doi.org/10.1080/15376516.2016.1223241

Luty S, Latuszynska J, Halliop J, Tochman A, Obuchowska D, Korczak B, Przylepa E, Bychawski E. 1997. Dermal toxicity of paraquat. Ann Agric Environ Med. 4:217-228.

Mangano EN, Hayley S. 2009. Inflammatory priming of the substantia nigra influences the impact of later paraquat exposure: Neuroimmune sensitization of neurodegeneration. Neurobiol Aging. 30(9):1361-1378. https://doi.org/10.1016/j.neurobiolaging.2007.11.020

Mangano EN, Litteljohn D, So R, Nelson E, Peters S, Bethune C, Bobyn J, Hayley S. 2012. Interferon-gamma plays a role in paraquat-induced neurodegeneration involving oxidative and proinflammatory pathways. Neurobiol Aging. 33(7):1411-1426. https://doi.org/10.1016/j.neurobiolaging.2011.02.016

Mangano EN, Peters S, Litteljohn D, So R, Bethune C, Bobyn J, Clarke M, Hayley S. 2011. Granulocyte macrophage-colony stimulating factor protects against substantia nigra dopaminergic cell loss in an environmental toxin model of Parkinson's disease. Neurobiol Dis. 43(1):99-112. https://doi.org/10.1016/j.nbd.2011.02.011

Manning-Bog AB, McCormack AL, Purisai MG, Bolin LM, Di Monte DA. 2003. Alpha-synuclein overexpression protects against paraquat-induced neurodegeneration. J Neurosci. 23(8):3095-3099.

Martin CA, Barajas A, Lawless G, Lawal HO, Assani K, Lumintang YP, Nunez V, Krantz DE. 2014. Synergistic effects on dopamine cell death in a Drosophila model of chronic toxin exposure. Neurotoxicology. 44:344-351. https://doi.org/10.1016/j.neuro.2014.08.005

Martinez-Perez DA, Jimenez-Del-Rio M, Velez-Pardo C. 2018. Epigallocatechin-3-gallate protects and prevents paraquat-induced oxidative stress and neurodegeneration in knockdown dj-1-beta Drosophila melanogaster. Neurotox Res. 34(3):401-416. https://doi.org/10.1007/s12640-018-9899-x

McCormack AL, Atienza JG, Johnston LC, Andersen JK, Vu S, Di Monte DA. 2005. Role of oxidative stress in paraquat-induced dopaminergic cell degeneration. J Neurochem. 93(4):1030-1037. https://doi.org/10.1111/j.1471-4159.2005.03088.x

McCormack AL, Atienza JG, Langston JW, Di Monte DA. 2006. Decreased susceptibility to oxidative stress underlies the resistance of specific dopaminergic cell populations to paraquat-induced degeneration. Neuroscience. 141(2):929-937. https://doi.org/10.1016/j.neuroscience.2006.03.069

McCormack AL, Di Monte DA. 2003. Effects of L-dopa and other amino acids against paraquat-induced nigrostriatal degeneration. J Neurochem. 85(1):82-86. https://doi.org/10.1046/j.1471-4159.2003.01621.x

McCormack AL, Thiruchelvam M, Manning-Bog AB, Thiffault C, Langston JW, Cory-Slechta DA, Di Monte DA. 2002. Environmental risk factors and Parkinson's disease: Selective degeneration of nigral dopaminergic neurons caused by the herbicide paraquat. Neurobiol Dis. 10(2):119-127.

Minnema DJ, Travis KZ, Breckenridge CB, Sturgess NC, Butt M, Wolf JC, Zadory D, Beck MJ, Mathews JM, Tisdel MO et al. 2014. Dietary administration of paraquat for 13 weeks does not result in a loss of dopaminergic neurons in the substantia nigra of C57BL/6J mice. Regul Toxicol Pharm. 68(2):250-258. https://doi.org/10.1016/j.yrtph.2013.12.010

Miranda-Contreras L, Davila-Ovalles R, Benitez-Diaz P, Pena-Contreras Z, Palacios-Pru E. 2005. Effects of prenatal paraquat and mancozeb exposure on amino acid synaptic transmission in developing mouse cerebellar cortex. Brain Res Dev Brain Res. 160(1):19-27. https://doi.org/10.1016/j.devbrainres.2005.08.001

Mitra S, Chakrabarti N, Bhattacharyya A. 2011. Differential regional expression patterns of alpha-synuclein, TNF-alpha, and IL-1beta; and variable status of dopaminergic neurotoxicity in mouse brain after paraquat treatment. J Neuroinflammation. 8:163. https://doi.org/10.1186/1742-2094-8-163

Mollace V, Iannone M, Muscoli C, Palma E, Granato T, Rispoli V, Nistico R, Rotiroti D, Salvemini D. 2003. The role of oxidative stress in paraquat-induced neurotoxicity in rats: Protection by non peptidyl superoxide dismutase mimetic. Neurosci Lett. 335(3):163-166. https://doi.org/10.1016/s0304-3940(02)01168-0

Müller TE, Nunes ME, Menezes CC, Marins AT, Leitemperger J, Gressler ACL, Carvalho FB, de Freitas CM, Quadros VA, Fachinetto R. 2018. Sodium selenite prevents paraquat-induced neurotoxicity in zebrafish. Mol Neurobiol. 55(3):1928-1941.

Muthukumaran K, Leahy S, Harrison K, Sikorska M, Sandhu JK, Cohen J, Keshan C, Lopatin D, Miller H, Borowy-Borowski H et al. 2014. Orally delivered water soluble Coenzyme Q10 (Ubisol-Q10) blocks on-going neurodegeneration in rats exposed to paraquat: Potential for therapeutic application in Parkinson's disease. BMC Neurosci. 15:21. https://doi.org/10.1186/1471-2202-15-21

Naudet N, Antier E, Gaillard D, Morignat E, Lakhdar L, Baron T, Bencsik A. 2017. Oral exposure to paraquat triggers earlier expression of phosphorylated alpha-synuclein in the enteric nervous system of A53T mutant human alpha-synuclein transgenic mice. J Neuropathol Exp Neurol. 76(12):1046-1057. https://doi.org/10.1093/jnen/nlx092

Nellore J, Nandita P. 2015. Paraquat exposure induces behavioral deficits in larval zebrafish during the window of dopamine neurogenesis. Toxicol Rep. 2:950-956.

Nellore J, Shajan A, Antony D, Cynthia PP, Karthick R, Namasivayam S. 2015. Proteinaceous compounds from fragaria ananassa fruit attenuates paraquat induced Parkinson like locomotor and mitochondrial alterations in Zebrafish. Int J Pharm Pharm Sci. 7:246-251.

Niveditha S, Ramesh SR, Shivanandappa T. 2017. Paraquat-induced movement disorder in relation to oxidative stress-mediated neurodegeneration in the brain of Drosophila melanogaster. Neurochem Res. 42(11):3310-3320. https://doi.org/10.1007/s11064-017-2373-y

Nixon AM, Meadowcroft MD, Neely EB, Snyder AM, Purnell CJ, Wright J, Lamendella R, Nandar W, Huang X, Connor JR. 2018. HFE genotype restricts the response to paraquat in a mouse model of neurotoxicity. J Neurochem. 145(4):299-311. https://doi.org/10.1111/jnc.14299

Nuber S, Tadros D, Fields J, Overk CR, Ettle B, Kosberg K, Mante M, Rockenstein E, Trejo M, Masliah E. 2014. Environmental neurotoxic challenge of conditional alpha-synuclein transgenic mice predicts a dopaminergic olfactory-striatal interplay in early PD. Acta Neuropathol. 127(4):477-494. https://doi.org/10.1007/s00401-014-1255-5

Nunes ME, Müller TE, Braga MM, Fontana BD, Quadros VA, Marins A, Rodrigues C, Menezes C, Rosemberg DB, Loro VL. 2017. Chronic treatment with paraquat induces brain injury, changes in antioxidant defenses system, and modulates behavioral functions in zebrafish. Mol Neurobiol. 54(6):3925-3934. https://doi.org/10.1007/s12035-016-9919-x

Ortega-Arellano HF, Jimenez-Del-Rio M, Velez-Pardo C. 2011. Life span and locomotor activity modification by glucose and polyphenols in Drosophila melanogaster chronically exposed to oxidative stress-stimuli: Implications in Parkinson’s disease. Neurochem Res. 36(6):1073-1086.

Ossowska K, Smialowska M, Kuter K, Wieronska J, Zieba B, Wardas J, Nowak P, Dabrowska J, Bortel A, Biedka I et al. 2006. Degeneration of dopaminergic mesocortical neurons and activation of compensatory processes induced by a long-term paraquat administration in rats: Implications for Parkinson's disease. Neuroscience. 141(4):2155-2165. https://doi.org/10.1016/j.neuroscience.2006.05.039

Ossowska K, Wardas J, Smialowska M, Kuter K, Lenda T, Wieronska JM, Zieba B, Nowak P, Dabrowska J, Bortel A et al. 2005. A slowly developing dysfunction of dopaminergic nigrostriatal neurons induced by long-term paraquat administration in rats: An animal model of preclinical stages of Parkinson's disease? Eur J Neurosci. 22(6):1294-1304. https://doi.org/10.1111/j.1460-9568.2005.04301.x

Park J, Kim SY, Cha GH, Lee SB, Kim S, Chung J. 2005. Drosophila DJ-1 mutants show oxidative stress-sensitive locomotive dysfunction. Gene. 361:133-139. https://doi.org/10.1016/j.gene.2005.06.040

Peled-Kamar M, Lotem J, Wirguin I, Weiner L, Hermalin A, Groner Y. 1997. Oxidative stress mediates impairment of muscle function in transgenic mice with elevated level of wild-type Cu/Zn superoxide dismutase. Proc Natl Acad Sci U S A. 94(8):3883-3887. https://doi.org/10.1073/pnas.94.8.3883

Peng J, Mao XO, Stevenson FF, Hsu M, Andersen JK. 2004. The herbicide paraquat induces dopaminergic nigral apoptosis through sustained activation of the JNK pathway. J Biol Chem. 279(31):32626-32632. https://doi.org/10.1074/jbc.M404596200

Peng J, Oo ML, Andersen JK. 2010. Synergistic effects of environmental risk factors and gene mutations in Parkinson's disease accelerate age-related neurodegeneration. J Neurochem. 115(6):1363-1373. https://doi.org/10.1111/j.1471-4159.2010.07036.x

Peng J, Peng L, Stevenson FF, Doctrow SR, Andersen JK. 2007. Iron and paraquat as synergistic environmental risk factors in sporadic Parkinson's disease accelerate age-related neurodegeneration. J Neurosci. 27(26):6914-6922. https://doi.org/10.1523/jneurosci.1569-07.2007

Phom L, Achumi B, Alone DP, Muralidhara, Yenisetti SC. 2014. Curcumin's neuroprotective efficacy in Drosophila model of idiopathic Parkinson's disease is phase specific: Implication of its therapeutic effectiveness. Rejuvenation Res. 17(6):481-489. https://doi.org/10.1089/rej.2014.1591

Prasad K, Tarasewicz E, Mathew J, Strickland PA, Buckley B, Richardson JR, Richfield EK. 2009. Toxicokinetics and toxicodynamics of paraquat accumulation in mouse brain. Exp Neurol. 215(2):358-367. https://doi.org/10.1016/j.expneurol.2008.11.003

Purisai MG, McCormack AL, Cumine S, Li J, Isla MZ, Di Monte DA. 2007. Microglial activation as a priming event leading to paraquat-induced dopaminergic cell degeneration. Neurobiol Dis. 25(2):392-400. https://doi.org/10.1016/j.nbd.2006.10.008

Qin X, Wu Q, Lin L, Sun A, Liu S, Li X, Cao X, Gao T, Luo P, Zhu X et al. 2015. Soluble epoxide hydrolase deficiency or inhibition attenuates MPTP-induced Parkinsonism. Mol Neurobiol. 52(1):187-195. https://doi.org/10.1007/s12035-014-8833-3

Quintero-Espinosa D, Jimenez-Del-Rio M, Velez-Pardo C. 2017. Knockdown transgenic Lrrk Drosophila resists paraquat-induced locomotor impairment and neurodegeneration: A therapeutic strategy for Parkinson's disease. Brain Res. 1657:253-261. https://doi.org/10.1016/j.brainres.2016.12.023

Rappold PM, Cui M, Chesser AS, Tibbett J, Grima JC, Duan L, Sen N, Javitch JA, Tieu K. 2011. Paraquat neurotoxicity is mediated by the dopamine transporter and organic cation transporter-3. Proc Natl Acad Sci U S A. 108(51):20766-20771. https://doi.org/10.1073/pnas.1115141108

Reeves R, Thiruchelvam M, Baggs RB, Cory-Slechta DA. 2003. Interactions of paraquat and triadimefon: Behavioral and neurochemical effects. Neurotoxicology. 24(6):839-850. https://doi.org/10.1016/s0161-813x(03)00057-3

Ren JP, Zhao YW, Sun XJ. 2009. Toxic influence of chronic oral administration of paraquat on nigrostriatal dopaminergic neurons in C57BL/6 mice. Chin Med J. 122(19):2366-2371.

Rodriguez-Rocha H, Garcia Garcia A, Zavala-Flores L, Li S, Madayiputhiya N, Franco R. 2012. Glutaredoxin 1 protects dopaminergic cells by increased protein glutathionylation in experimental Parkinson's disease. Antioxid Redox Signal. 17(12):1676-1693. https://doi.org/10.1089/ars.2011.4474

Rojo AI, Cavada C, de Sagarra MR, Cuadrado A. 2007. Chronic inhalation of rotenone or paraquat does not induce Parkinson's disease symptoms in mice or rats. Exp Neurol. 208(1):120-126. https://doi.org/10.1016/j.expneurol.2007.07.022

Rudyk CA, McNeill J, Prowse N, Dwyer Z, Farmer K, Litteljohn D, Caldwell W, Hayley S. 2017. Age and chronicity of administration dramatically influenced the impact of low dose paraquat exposure on behavior and hypothalamic-pituitary-adrenal activity. Front Aging Neurosci. 9:222. https://doi.org/10.3389/fnagi.2017.00222

S N, Shivanandappa T. 2018. Neuroprotective action of 4-Hydroxyisophthalic acid against paraquat-induced motor impairment involves amelioration of mitochondrial damage and neurodegeneration in Drosophila. Neurotoxicology. 66:160-169. https://doi.org/10.1016/j.neuro.2018.04.006

Satayavivad J, Sirapat W, Thiantanawat A. 1997. Neurological effects of chronic exposure to low doses of paraquat in rats. Res Commun Pharmacol Toxicol. 2:269-282.

Satpute RM, Pawar PP, Puttewar S, Sawale SD, Ambhore PD. 2017. Effect of resveratrol and tetracycline on the subacute paraquat toxicity in mice. Hum Exp Toxicol. 36(12):1303-1314. https://doi.org/10.1177/0960327116688070

Shaikh KT, Yang A, Youshin E, Schmid S. 2015. Transgenic LRRK2 (R1441G) rats-a model for Parkinson disease? PeerJ. 3:e945. https://doi.org/10.7717/peerj.945

Shepherd KR, Lee ES, Schmued L, Jiao Y, Ali SF, Oriaku ET, Lamango NS, Soliman KF, Charlton CG. 2006. The potentiating effects of 1-methyl-4-phenyl-1,2,3,6-tetrahydropyridine (MPTP) on paraquat-induced neurochemical and behavioral changes in mice. Pharmacol Biochem Behav. 83(3):349-359. https://doi.org/10.1016/j.pbb.2006.02.013

Shukla AK, Pragya P, Chaouhan HS, Patel DK, Abdin MZ, Kar Chowdhuri D. 2014. Mutation in Drosophila methuselah resists paraquat induced Parkinson-like phenotypes. Neurobiol Aging. 35(10):2419.e2411-2419.e2416. https://doi.org/10.1016/j.neurobiolaging.2014.04.008

Shukla AK, Pragya P, Chaouhan HS, Tiwari AK, Patel DK, Abdin MZ, Chowdhuri DK. 2014. Heat shock protein-70 (Hsp-70) suppresses paraquat-induced neurodegeneration by inhibiting JNK and caspase-3 activation in Drosophila model of Parkinson's disease. PLoS One. 9(6):e98886. https://doi.org/10.1371/journal.pone.0098886

Sidlauskaite E, Gibson JW, Megson IL, Whitfield PD, Tovmasyan A, Batinic-Haberle I, Murphy MP, Moult PR, Cobley JN. 2018. Mitochondrial ROS cause motor deficits induced by synaptic inactivity: Implications for synapse pruning. Redox Biol. 16:344-351. https://doi.org/10.1016/j.redox.2018.03.012

Smeyne RJ, Breckenridge CB, Beck M, Jiao Y, Butt MT, Wolf JC, Zadory D, Minnema DJ, Sturgess NC, Travis KZ et al. 2016. Assessment of the effects of MPTP and paraquat on dopaminergic neurons and microglia in the substantia nigra pars compacta of C57BL/6 mice. PLoS One. 11(10):e0164094. https://doi.org/10.1371/journal.pone.0164094

Soares JJ, Rodrigues DT, Goncalves MB, Lemos MC, Gallarreta MS, Bianchini MC, Gayer MC, Puntel RL, Roehrs R, Denardin ELG. 2017. Paraquat exposure-induced Parkinson's disease-like symptoms and oxidative stress in Drosophila melanogaster: Neuroprotective effect of Bougainvillea glabra Choisy. Biomed Pharmacother. 95:245-251. https://doi.org/10.1016/j.biopha.2017.08.073

Somayajulu-Nitu M, Sandhu JK, Cohen J, Sikorska M, Sridhar TS, Matei A, Borowy-Borowski H, Pandey S. 2009. Paraquat induces oxidative stress, neuronal loss in substantia nigra region and parkinsonism in adult rats: Neuroprotection and amelioration of symptoms by water-soluble formulation of coenzyme Q10. BMC Neurosci. 10:88. https://doi.org/10.1186/1471-2202-10-88

Songin M, Strosznajder JB, Fital M, Kuter K, Kolasiewicz W, Nowak P, Ossowska K. 2011. Glycogen synthase kinase 3beta and its phosphorylated form (Y216) in the paraquat-induced model of parkinsonism. Neurotox Res. 19(1):162-171. https://doi.org/10.1007/s12640-010-9153-7

Su C, Niu P. 2015. Low doses of single or combined agrichemicals induces alpha-synuclein aggregation in nigrostriatal system of mice through inhibition of proteasomal and autophagic pathways. Int J Clin Exp Med. 8(11):20508-20515.

Tang SP, Salam SKN, Jaafar H, Gan SH, Muzaimi M, Sulaiman SA. 2017. Tualang honey protects the rat midbrain and lung against repeated paraquat exposure. Oxid Med Cell Longev. https://doi.org/10.1155/2017/4605782

Thiruchelvam M, Brockel BJ, Richfield EK, Baggs RB, Cory-Slechta DA. 2000. Potentiated and preferential effects of combined paraquat and maneb on nigrostriatal dopamine systems: Environmental risk factors for Parkinson's disease? Brain Res. 873(2):225-234. https://doi.org/10.1016/s0006-8993(00)02496-3

Thiruchelvam M, McCormack A, Richfield EK, Baggs RB, Tank AW, Di Monte DA, Cory-Slechta DA. 2003. Age-related irreversible progressive nigrostriatal dopaminergic neurotoxicity in the paraquat and maneb model of the Parkinson's disease phenotype. Eur J Neurosci. 18(3):589-600.

Thiruchelvam M, Richfield EK, Baggs RB, Tank AW, Cory-Slechta DA. 2000. The nigrostriatal dopaminergic system as a preferential target of repeated exposures to combined paraquat and maneb: Implications for Parkinson's disease. J Neurosci. 20(24):9207-9214.

Thiruchelvam M, Richfield EK, Goodman BM, Baggs RB, Cory-Slechta DA. 2002. Developmental exposure to the pesticides paraquat and maneb and the Parkinson's disease phenotype. Neurotoxicology. 23(4-5):621-633.

Wang Q, Ren N, Cai Z, Lin Q, Wang Z, Zhang Q, Wu S, Li H. 2017. Paraquat and MPTP induce neurodegeneration and alteration in the expression profile of microRNAs: The role of transcription factor Nrf2. NPJ Parkinson’s Dis. 3:31. https://doi.org/10.1038/s41531-017-0033-1

Wang R, Zhao X, Xu J, Wen Y, Li A, Lu M, Zhou J. 2018. Astrocytic JWA deletion exacerbates dopaminergic neurodegeneration by decreasing glutamate transporters in mice. Cell Death Dis. 9(3):352. https://doi.org/10.1038/s41419-018-0381-8

Wang XH, Souders CL, 2nd, Zhao YH, Martyniuk CJ. 2018. Paraquat affects mitochondrial bioenergetics, dopamine system expression, and locomotor activity in zebrafish (Danio rerio). Chemosphere. 191:106-117. https://doi.org/10.1016/j.chemosphere.2017.10.032

Watson MB, Nobuta H, Abad C, Lee SK, Bala N, Zhu C, Richter F, Chesselet MF, Waschek JA. 2013. PACAP deficiency sensitizes nigrostriatal dopaminergic neurons to paraquat-induced damage and modulates central and peripheral inflammatory activation in mice. Neuroscience. 240:277-286. https://doi.org/10.1016/j.neuroscience.2013.03.002

Widdowson PS, Farnworth MJ, Upton R, Simpson MG. 1996. No changes in behaviour, nigro-striatal system neurochemistry or neuronal cell death following toxic multiple oral paraquat administration to rats. Hum Exp Toxicol. 15(7):583-591. https://doi.org/10.1177/096032719601500706

Willis GL, Moore C, Armstrong SM. 2014. Parkinson's disease, lights and melanocytes: Looking beyond the retina. Sci Rep. 4:3921. https://doi.org/10.1038/srep03921

Woolley DE, Gietzen DW, Gee SJ, Magdalou J, Hammock BD. 1989. Does paraquat (PQ) mimic MPP+ toxicity? Proc West Pharmacol Soc. 32:191-193.

Yadav SK, Prakash J, Chouhan S, Singh SP. 2013. Mucuna pruriens seed extract reduces oxidative stress in nigrostriatal tissue and improves neurobehavioral activity in paraquat-induced Parkinsonian mouse model. Neurochem Int. 62(8):1039-1047. https://doi.org/10.1016/j.neuint.2013.03.015

Yadav SK, Rai SN, Singh SP. 2017. Mucuna pruriens reduces inducible nitric oxide synthase expression in Parkinsonian mice model. J Chem Neuroanat. 80:1-10. https://doi.org/10.1016/j.jchemneu.2016.11.009

Yang W, Chen L, Ding Y, Zhuang X, Kang UJ. 2007. Paraquat induces dopaminergic dysfunction and proteasome impairment in DJ-1-deficient mice. Hum Mol Genet. 16(23):2900-2910. https://doi.org/10.1093/hmg/ddm249

Yin L, Lu L, Prasad K, Richfield EK, Unger EL, Xu J, Jones BC. 2011. Genetic-based, differential susceptibility to paraquat neurotoxicity in mice. Neurotoxicol Teratol. 33(3):415-421. https://doi.org/10.1016/j.ntt.2011.02.012

Zhao F, Wang W, Wang C, Siedlak SL, Fujioka H, Tang B, Zhu X. 2017. Mfn2 protects dopaminergic neurons exposed to paraquat both in vitro and in vivo: Implications for idiopathic Parkinson's disease. Biochim Biophys Acta. 1863(6):1359-1370. https://doi.org/10.1016/j.bbadis.2017.02.016

Zhao X, Wang R, Xiong J, Yan D, Li A, Wang S, Xu J, Zhou J. 2017. JWA antagonizes paraquat-induced neurotoxicity via activation of Nrf2. Toxicol Lett. 277:32-40. https://doi.org/10.1016/j.toxlet.2017.04.011

Zhou H, Huang C, Tong J, Xia XG. 2011. Early exposure to paraquat sensitizes dopaminergic neurons to subsequent silencing of PINK1 gene expression in mice. Int J Biol Sci. 7(8):1180-1187. https://doi.org/10.7150/ijbs.7.1180

## E.4 Animal Studies: Secondary Endpoints

Certain studies in this list are also included in the Human Studies: Primary Endpoints list, the Animal Studies: Primary Endpoints list, and the In Vitro Studies list if they contained data relating to those endpoints in addition to animal secondary endpoints.

Ait-Bali Y, Ba-M'hamed S, Bennis M. 2016. Prenatal paraquat exposure induces neurobehavioral and cognitive changes in mice offspring. Environ Toxicol Pharmacol. 48:53-62. https://doi.org/10.1016/j.etap.2016.10.008

Ajjuri RR, O'Donnell JM. 2013. Novel whole-tissue quantitative assay of nitric oxide levels in Drosophila neuroinflammatory response. J Vis Exp. (82):50892. https://doi.org/10.3791/50892

Anselmi L, Toti L, Bove C, Hampton J, Travagli RA. 2017. A nigro-vagal pathway controls gastric motility and is affected in a rat model of Parkinsonism. Gastroenterology. 153(6):1581-1593. https://doi.org/10.1053/j.gastro.2017.08.069

Attia HN, Maklad YA. 2018. Neuroprotective effects of coenzyme Q10 on paraquat-induced Parkinson's disease in experimental animals. Behav Pharmacol. 29(1):79-86. https://doi.org/10.1097/fbp.0000000000000342

Bagetta G, Iannone M, Vecchio I, Rispoli V, Rotiroti D, Nistico G. 1994. Neurodegeneration produced by intrahippocampal injection of paraquat is reduced by systemic administration of the 21-aminosteroid U74389F in rats. Free Radic Res. 21(2):85-93.

Bajo-Graneras R, Ganfornina MD, Martin-Tejedor E, Sanchez D. 2011. Apolipoprotein D mediates autocrine protection of astrocytes and controls their reactivity level, contributing to the functional maintenance of paraquat-challenged dopaminergic systems. Glia. 59(10):1551-1566. https://doi.org/10.1002/glia.21200

Bajo-Graneras R, Sanchez D, Gutierrez G, Gonzalez C, Do Carmo S, Rassart E, Ganfornina MD. 2011. Apolipoprotein D alters the early transcriptional response to oxidative stress in the adult cerebellum. J Neurochem. 117(6):949-960. https://doi.org/10.1111/j.1471-4159.2011.07266.x

Barbeau A, Dallaire L, Buu NT, Poirier J, Rucinska E. 1985. Comparative behavioral, biochemical and pigmentary effects of MPTP, MPP+ and paraquat in Rana pipiens. Life Sci. 37(16):1529-1538. https://doi.org/10.1016/0024-3205(85)90185-7

Barlow BK, Richfield EK, Cory-Slechta DA, Thiruchelvam M. 2004. A fetal risk factor for Parkinson's disease. Dev Neurosci. 26(1):11-23. https://doi.org/10.1159/000080707

Benzi G, Marzatico F, Pastoris O, Villa RF. 1990. Influence of oxidative stress on the age-linked alterations of the cerebral glutathione system. J Neurosci Res. 26(1):120-128. https://doi.org/10.1002/jnr.490260116

Bobyn J, Mangano EN, Gandhi A, Nelson E, Moloney K, Clarke M, Hayley S. 2012. Viral-toxin interactions and Parkinson's disease: Poly I:C priming enhanced the neurodegenerative effects of paraquat. J Neuroinflammation. 9:86. https://doi.org/10.1186/1742-2094-9-86

Bortolotto JW, Cognato GP, Christoff RR, Roesler LN, Leite CE, Kist LW, Bogo MR, Vianna MR, Bonan CD. 2014. Long-term exposure to paraquat alters behavioral parameters and dopamine levels in adult zebrafish (Danio rerio). Zebrafish. 11(2):142-153. https://doi.org/10.1089/zeb.2013.0923

Breckenridge CB, Sturgess NC, Butt M, Wolf JC, Zadory D, Beck M, Mathews JM, Tisdel MO, Minnema D, Travis KZ et al. 2013. Pharmacokinetic, neurochemical, stereological and neuropathological studies on the potential effects of paraquat in the substantia nigra pars compacta and striatum of male C57BL/6J mice. Neurotoxicology. 37:1-14. https://doi.org/10.1016/j.neuro.2013.03.005

Brooks AI, Chadwick CA, Gelbard HA, Cory-Slechta DA, Federoff HJ. 1999. Paraquat elicited neurobehavioral syndrome caused by dopaminergic neuron loss. Brain Res. 823(1-2):1-10. https://doi.org/10.1016/s0006-8993(98)01192-5

Chanyachukul T, Yoovathaworn K, Thongsaard W, Chongthammakun S, Navasumrit P, Satayavivad J. 2004. Attenuation of paraquat-induced motor behavior and neurochemical disturbances by L-valine in vivo. Toxicol Lett. 150(3):259-269. https://doi.org/10.1016/j.toxlet.2004.02.007

Chaudhuri A, Bowling K, Funderburk C, Lawal H, Inamdar A, Wang Z, O'Donnell JM. 2007. Interaction of genetic and environmental factors in a Drosophila parkinsonism model. J Neurosci. 27(10):2457-2467. https://doi.org/10.1523/jneurosci.4239-06.2007

Chen AY, Tully T. 2018. A stress-enhanced model for discovery of disease-modifying gene: Ece1-suppresses the toxicity of alpha-synuclein A30P. Neurobiol Dis. 114:153-163. https://doi.org/10.1016/j.nbd.2018.03.003

Chen LJ, Yoo SE, Na R, Liu YH, Ran QT. 2012. Cognitive impairment and increased Aβ levels induced by paraquat exposure are attenuated by enhanced removal of mitochondrial H2O2. Neurobiol Aging. 33(2). https://doi.org/10.1016/j.neurobiolaging.2011.01.008

Chen P, Chen Z, Li A, Lou XC, Wu XK, Zhao CJ, Wang SL, Liang LP. 2008. Catalytic metalloporphyrin protects against paraquat neurotoxicity in vivo. Biomed Environ Sci. 21(3):233-238. https://doi.org/10.1016/s0895-3988(08)60035-5

Chen Q, Niu Y, Zhang R, Guo H, Gao Y, Li Y, Liu R. 2010. The toxic influence of paraquat on hippocampus of mice: Involvement of oxidative stress. Neurotoxicology. 31(3):310-316. https://doi.org/10.1016/j.neuro.2010.02.006

Chinta SJ, Woods G, Demaria M, Rane A, Zou Y, McQuade A, Rajagopalan S, Limbad C, Madden DT, Campisi J et al. 2018. Cellular senescence is induced by the environmental neurotoxin paraquat and contributes to neuropathology linked to Parkinson's disease. Cell Rep. 22(4):930-940. https://doi.org/10.1016/j.celrep.2017.12.092

Choi HS, An JJ, Kim SY, Lee SH, Kim DW, Yoo KY, Won MH, Kang TC, Kwon HJ, Kang JH et al. 2006. PEP-1-SOD fusion protein efficiently protects against paraquat-induced dopaminergic neuron damage in a Parkinson disease mouse model. Free Radic Biol Med. 41(7):1058-1068. https://doi.org/10.1016/j.freeradbiomed.2006.06.006

Cicchetti F, Lapointe N, Roberge-Tremblay A, Saint-Pierre M, Jimenez L, Ficke BW, Gross RE. 2005. Systemic exposure to paraquat and maneb models early Parkinson's disease in young adult rats. Neurobiol Dis. 20(2):360-371. https://doi.org/10.1016/j.nbd.2005.03.018

Cosenza M, Bidanset J, Johnson D. 1994. Effects of paraquat on the midbrain micromass cell culture system. In Vitro Toxicol. 7(4):313-320.

Costa KM, Maciel IS, Kist LW, Campos MM, Bogo MR. 2014. Pharmacological inhibition of CXCR2 chemokine receptors modulates paraquat-induced intoxication in rats. PLoS One. 9(8):e105740. https://doi.org/10.1371/journal.pone.0105740

Coughlan C, Walker DI, Lohr KM, Richardson JR, Saba LM, Caudle WM, Fritz KS, Roede JR. 2015. Comparative proteomic analysis of carbonylated proteins from the striatum and cortex of pesticide-treated mice. Parkinsons Dis. 2015:812532. https://doi.org/10.1155/2015/812532

Cristovao AC, Choi DH, Baltazar G, Beal MF, Kim YS. 2009. The role of NADPH oxidase 1-derived reactive oxygen species in paraquat-mediated dopaminergic cell death. Antioxid Redox Signal. 11(9):2105-2118. https://doi.org/10.1089/ars.2009.2459

Cristovao AC, Guhathakurta S, Bok E, Je G, Yoo SD, Choi DH, Kim YS. 2012. NADPH oxidase 1 mediates alpha-synucleinopathy in Parkinson's disease. J Neurosci. 32(42):14465-14477. https://doi.org/10.1523/jneurosci.2246-12.2012

Czerniczyniec A, Karadayian AG, Bustamante J, Cutrera RA, Lores-Arnaiz S. 2011. Paraquat induces behavioral changes and cortical and striatal mitochondrial dysfunction. Free Radic Biol Med. 51(7):1428-1436. https://doi.org/10.1016/j.freeradbiomed.2011.06.034

Czerniczyniec A, Lanza EM, Karadayian AG, Bustamante J, Lores-Arnaiz S. 2015. Impairment of striatal mitochondrial function by acute paraquat poisoning. J Bioenerg Biomembr. 47(5):395-408. https://doi.org/10.1007/s10863-015-9624-x

Czerniczyniec A, Lores-Arnaiz S, Bustamante J. 2013. Mitochondrial susceptibility in a model of paraquat neurotoxicity. Free Radic Res. 47(8):614-623. https://doi.org/10.3109/10715762.2013.806797

de Oliveira Souza A, Couto-Lima CA, Rosa Machado MC, Espreafico EM, Pinheiro Ramos RG, Alberici LC. 2017. Protective action of Omega-3 on paraquat intoxication in Drosophila melanogaster. J Toxicol Environ Health A. 80(19-21):1050-1063. https://doi.org/10.1080/15287394.2017.1357345

Degori N, Froio F, Strongoli MC, Defrancesco A, Calo M, Nistico G. 1988. Behavioral and electrocortical changes induced by paraquat after injection in specific areas of the brain of the rat. Neuropharmacology. 27(2):201-207. https://doi.org/10.1016/0028-3908(88)90171-2

Djukic M, Jovanovic MC, Ninkovic M, Vasiljevic I, Jovanovic M. 2007. The role of nitric oxide in paraquat-induced oxidative stress in rat striatum. Ann Agric Environ Med. 14(2):247-252.

Djukic MM, Jovanovic MD, Ninkovic M, Stevanovic I, Ilic K, Curcic M, Vekic J. 2012. Protective role of glutathione reductase in paraquat induced neurotoxicity. Chem Biol Interact. 199(2):74-86. https://doi.org/10.1016/j.cbi.2012.05.008

Ellwanger JH, Molz P, Dallemole DR, Pereira dos Santos A, Müller TE, Cappelletti L, Goncalves da Silva M, Franke SI, Pra D, Pegas Henriques JA. 2015. Selenium reduces bradykinesia and DNA damage in a rat model of Parkinson's disease. Nutrition. 31(2):359-365. https://doi.org/10.1016/j.nut.2014.07.004

Endo T, Hara S, Kano S, Kuriwa F. 1988. Effects of a paraquat-containing herbicide, gramoxon®, on the central monoamines and acetylcholine in mice. Res Commun Psychol Psychiatr Behav. 13(4):261-270.

Fahim MA, Shehab S, Nemmar A, Adem A, Dhanasekaran S, Hasan MY. 2013. Daily subacute paraquat exposure decreases muscle function and substantia nigra dopamine level. Physiol Res. 62(3):313-321.

Faro LR, Alfonso M, Cervantes R, Duran R. 2009. Comparative effects of pesticides on in vivo dopamine release in freely moving rats. Basic Clin Pharmacol Toxicol. 105(6):395-400. https://doi.org/10.1111/j.1742-7843.2009.00468.x

Fernagut PO, Hutson CB, Fleming SM, Tetreaut NA, Salcedo J, Masliah E, Chesselet MF. 2007. Behavioral and histopathological consequences of paraquat intoxication in mice: Effects of alpha-synuclein over-expression. Synapse. 61(12):991-1001. https://doi.org/10.1002/syn.20456

Filograna R, Godena VK, Sanchez-Martinez A, Ferrari E, Casella L, Beltramini M, Bubacco L, Whitworth AJ, Bisaglia M. 2016. Uperoxide dismutase (SOD)-mimetic M40403 is protective in cell and fly models of paraquat toxicity: Implications for Parkinson disease. J Biol Chem. 291(17):9257-9267. https://doi.org/10.1074/jbc.M115.708057

Finnerty NJ, O'Riordan SL, Lowry JP, Cloutier M, Wellstead P. 2013. Continuous real-time in vivo measurement of cerebral nitric oxide supports theoretical predictions of an irreversible switching in cerebral ROS after sufficient exposure to external toxins. J Parkinsons Dis. 3(3):351-362. https://doi.org/10.3233/jpd-130198

Fredriksson A, Fredriksson M, Eriksson P. 1993. Neonatal exposure to paraquat or MPTP induces permanent changes in striatum dopamine and behavior in adult mice. Toxicol Appl Pharmacol. 122(2):258-264. https://doi.org/10.1006/taap.1993.1194

Goers J, Manning-Bog AB, McCormack AL, Millett IS, Doniach S, Di Monte DA, Uversky VN, Fink AL. 2003. Nuclear localization of alpha-synuclein and its interaction with histones. Biochemistry. 42(28):8465-8471. https://doi.org/10.1021/bi0341152

Gollamudi S, Johri A, Calingasan NY, Yang L, Elemento O, Beal MF. 2012. Concordant signaling pathways produced by pesticide exposure in mice correspond to pathways identified in human Parkinson's disease. PLoS One. 7(5):e36191. https://doi.org/10.1371/journal.pone.0036191

Goncalves C, Dos Santos DB, Portilho SS, Lopes MW, Ghizoni H, de Souza V, Mack JM, Naime AA, Dafre AL, de Souza Brocardo P et al. 2018. Lipopolysaccharide-induced striatal nitrosative stress and impaired social recognition memory are not magnified by paraquat coexposure. Neurochem Res. 43(3):745-759. https://doi.org/10.1007/s11064-018-2477-z

Gonzalez-Hunt CP, Leung MC, Bodhicharla RK, McKeever MG, Arrant AE, Margillo KM, Ryde IT, Cyr DD, Kosmaczewski SG, Hammarlund M et al. 2014. Exposure to mitochondrial genotoxins and dopaminergic neurodegeneration in Caenorhabditis elegans. PLoS One. 9(12):e114459. https://doi.org/10.1371/journal.pone.0114459

Gorkin V, Amanov K, Mamadiev M, Medvedev A, Khuzhamberdiev M. 1994. The biochemical-mechanisms of the toxic effects of some pyridine-derivatives .1. Study on the deamination of biogenic-amines and other nitrogenous compounds in paraquat intoxication. Arch Environ Contam Toxicol. 26(4):534-539. https://doi.org/10.1007/bf00214158

Gourgou E, Chronis N. 2016. Chemically induced oxidative stress affects ASH neuronal function and behavior in C-elegans. Sci Rep. 6. https://doi.org/10.1038/srep38147

Hosamani R, Krishna G, Muralidhara. 2016. Standardized Bacopa monnieri extract ameliorates acute paraquat-induced oxidative stress, and neurotoxicity in prepubertal mice brain. Nutr Neurosci. 19(10):434-446. https://doi.org/10.1179/1476830514y.0000000149

Hutson CB, Lazo CR, Mortazavi F, Giza CC, Hovda D, Chesselet MF. 2011. Traumatic brain injury in adult rats causes progressive nigrostriatal dopaminergic cell loss and enhanced vulnerability to the pesticide paraquat. J Neurotrauma. 28(9):1783-1801. https://doi.org/10.1089/neu.2010.1723

Iannone M, Ciriolo MR, Rotilio G, Nistico G. 1991. Intra-nigral infusion of Cu-free superoxide dismutase prevents paraquat-induced behavioural stimulation and ECoG epileptogenic discharges in rats. Neuropharmacology. 30(8):893-898.

Inamdar AA, Chaudhuri A, O'Donnell J. 2012. The protective effect of minocycline in a paraquat-induced Parkinson's disease model in drosophila is modified in altered genetic backgrounds. Parkinsons Dis. 2012:938528. https://doi.org/10.1155/2012/938528

Jadiya P, Nazir A. 2012. Environmental toxicants as extrinsic epigenetic factors for parkinsonism: Studies employing transgenic C. elegans model. CNS Neurol Disord Drug Targets. 11(8):976-983.

Janda E, Parafati M, Aprigliano S, Carresi C, Visalli V, Sacco I, Ventrice D, Mega T, Vadala N, Rinaldi S et al. 2013. The antidote effect of quinone oxidoreductase 2 inhibitor against paraquat-induced toxicity in vitro and in vivo. Br J Pharmacol. 168(1):46-59. https://doi.org/10.1111/j.1476-5381.2012.01870.x

Jhonsa DJ, Badgujar LB, Sutariya BK, Saraf MN. 2016. Neuroprotective effect of flavonoids against paraquat induced oxidative stress and neurotoxicity in Drosophila melanogaster. Curr Top Nutraceutical Res. 14(4):283-294.

Kang MJ, Gil SJ, Koh HC. 2009. Paraquat induces alternation of the dopamine catabolic pathways and glutathione levels in the substantia nigra of mice. Toxicol Lett. 188(2):148-152. https://doi.org/10.1016/j.toxlet.2009.03.026

Kang MJ, Gil SJ, Lee JE, Koh HC. 2010. Selective vulnerability of the striatal subregions of C57BL/6 mice to paraquat. Toxicol Lett. 195(2-3):127-134. https://doi.org/10.1016/j.toxlet.2010.03.011

Khwaja M, McCormack A, McIntosh JM, Di Monte DA, Quik M. 2007. Nicotine partially protects against paraquat-induced nigrostriatal damage in mice; link to α6β2* nAChRs. J Neurochem. 100(1):180-190. https://doi.org/10.1111/j.1471-4159.2006.04177.x

Krucek T, Korandova M, Sery M, Frydrychova RC, Krucek T, Korandova M, Szakosova K. 2015. Effect of low doses of herbicide paraquat on antioxidant defense in Drosophila. Arch Insect Biochem Physiol. 88(4):235-248. https://doi.org/10.1002/arch.21222

Kubo S, Tokunaga I, Yamamoto A, Morita K. 1999. Immunohistochemical studies on paraquat-induced damage to neuronal and glial cells in rat hippocampus. Acta Histochem Cytochem. 32(4):373-376. https://doi.org/10.1267/ahc.32.373

Kumar A, Ahmad I, Shukla S, Singh BK, Patel DK, Pandey HP, Singh C. 2010. Effect of zinc and paraquat co-exposure on neurodegeneration: Modulation of oxidative stress and expression of metallothioneins, toxicant responsive and transporter genes in rats. Free Radic Res. 44(8):950-965. https://doi.org/10.3109/10715762.2010.492832

Kumar A, Christian PK, Panchal K, Guruprasad BR, Tiwari AK. 2017. Supplementation of spirulina (Arthrospira platensis) improves lifespan and locomotor activity in paraquat-sensitive DJ-1beta(delta93) flies, a Parkinson's disease model in Drosophila melanogaster. J Diet Suppl. 14(5):573-588. https://doi.org/10.1080/19390211.2016.1275917

Kumar A, Singh BK, Ahmad I, Shukla S, Patel DK, Srivastava G, Kumar V, Pandey HP, Singh C. 2012. Involvement of NADPH oxidase and glutathione in zinc-induced dopaminergic neurodegeneration in rats: Similarity with paraquat neurotoxicity. Brain Res. 1438:48-64. https://doi.org/10.1016/j.brainres.2011.12.028

Kuter K, Nowak P, Golembiowska K, Ossowska K. 2010. Increased reactive oxygen species production in the brain after repeated low-dose pesticide paraquat exposure in rats. A comparison with peripheral tissues. Neurochem Res. 35(8):1121-1130. https://doi.org/10.1007/s11064-010-0163-x

Kuter K, Smialowska M, Wieronska J, Zieba B, Wardas J, Pietraszek M, Nowak P, Biedka I, Roczniak W, Konieczny J et al. 2007. Toxic influence of subchronic paraquat administration on dopaminergic neurons in rats. Brain Res. 1155:196-207. https://doi.org/10.1016/j.brainres.2007.04.018

Lavara-Culebras E, Paricio N. 2007. Drosophila DJ-1 mutants are sensitive to oxidative stress and show reduced lifespan and motor deficits. Gene. 400(1-2):158-165. https://doi.org/10.1016/j.gene.2007.06.013

Lawal HO, Chang HY, Terrell AN, Brooks ES, Pulido D, Simon AF, Krantz DE. 2010. The Drosophila vesicular monoamine transporter reduces pesticide-induced loss of dopaminergic neurons. Neurobiol Dis. 40(1):102-112. https://doi.org/10.1016/j.nbd.2010.05.008

Li H, Wu S, Wang Z, Lin W, Zhang C, Huang B. 2012. Neuroprotective effects of tert-butylhydroquinone on paraquat-induced dopaminergic cell degeneration in C57BL/6 mice and in PC12 cells. Arch Toxicol. 86(11):1729-1740. https://doi.org/10.1007/s00204-012-0935-y

Li HF, Zhao SX, Xing BP, Sun ML. 2015. Ulinastatin suppresses endoplasmic reticulum stress and apoptosis in the hippocampus of rats with acute paraquat poisoning. Neural Regen Res. 10(3):467-472. https://doi.org/10.4103/1673-5374.153698

Li X, Yin J, Cheng CM, Sun JL, Li Z, Wu YL. 2005. Paraquat induces selective dopaminergic nigrostriatal degeneration in aging C57BL/6 mice. Chin Med J. 118(16):1357-1361.

Liang LP, Kavanagh TJ, Patel M. 2013. Glutathione deficiency in Gclm null mice results in complex I inhibition and dopamine depletion following paraquat administration. Toxicol Sci. 134(2):366-373. https://doi.org/10.1093/toxsci/kft112

Ling LB, Chang Y, Liu CW, Lai PL, Hsu T. 2017. Oxidative stress intensity-related effects of cadmium (Cd) and paraquat (PQ) on UV-damaged-DNA binding and excision repair activities in zebrafish (Danio rerio) embryos. Chemosphere. 167:10-18. https://doi.org/10.1016/j.chemosphere.2016.09.068

Liou HH, Chen RC, Chen TH, Tsai YF, Tsai MC. 2001. Attenuation of paraquat-induced dopaminergic toxicity on the substantia nigra by (-)-deprenyl in vivo. Toxicol Appl Pharmacol. 172(1):37-43. https://doi.org/10.1006/taap.2001.9130

Liou HH, Chen RC, Tsai YF, Chen WP, Chang YC, Tsai MC. 1996. Effects of paraquat on the substantia nigra of the wistar rats: Neurochemical, histological, and behavioral studies. Toxicol Appl Pharmacol. 137(1):34-41. https://doi.org/10.1006/taap.1996.0054

Litteljohn D, Mangano E, Shukla N, Hayley S. 2009. Interferon-gamma deficiency modifies the motor and co-morbid behavioral pathology and neurochemical changes provoked by the pesticide paraquat. Neuroscience. 164(4):1894-1906. https://doi.org/10.1016/j.neuroscience.2009.09.025

Litteljohn D, Mangano EN, Hayley S. 2008. Cyclooxygenase-2 deficiency modifies the neurochemical effects, motor impairment and co-morbid anxiety provoked by paraquat administration in mice. Eur J Neurosci. 28(4):707-716. https://doi.org/10.1111/j.1460-9568.2008.06371.x

Litteljohn D, Nelson E, Bethune C, Hayley S. 2011. The effects of paraquat on regional brain neurotransmitter activity, hippocampal BDNF and behavioural function in female mice. Neurosci Lett. 502(3):186-191. https://doi.org/10.1016/j.neulet.2011.07.041

Liu D, Yang J, Li L, McAdoo DJ. 1995. Paraquat--a superoxide generator--kills neurons in the rat spinal cord. Free Radic Biol Med. 18(5):861-867.

Mak SK, McCormack AL, Manning-Bog AB, Cuervo AM, Di Monte DA. 2010. Lysosomal degradation of alpha-synuclein in vivo. J Biol Chem. 285(18):13621-13629. https://doi.org/10.1074/jbc.M109.074617

Mangano EN, Hayley S. 2009. Inflammatory priming of the substantia nigra influences the impact of later paraquat exposure: Neuroimmune sensitization of neurodegeneration. Neurobiol Aging. 30(9):1361-1378. https://doi.org/10.1016/j.neurobiolaging.2007.11.020

Mangano EN, Litteljohn D, So R, Nelson E, Peters S, Bethune C, Bobyn J, Hayley S. 2012. Interferon-gamma plays a role in paraquat-induced neurodegeneration involving oxidative and proinflammatory pathways. Neurobiol Aging. 33(7):1411-1426. https://doi.org/10.1016/j.neurobiolaging.2011.02.016

Mangano EN, Peters S, Litteljohn D, So R, Bethune C, Bobyn J, Clarke M, Hayley S. 2011. Granulocyte macrophage-colony stimulating factor protects against substantia nigra dopaminergic cell loss in an environmental toxin model of Parkinson's disease. Neurobiol Dis. 43(1):99-112. https://doi.org/10.1016/j.nbd.2011.02.011

Manning-Bog AB, McCormack AL, Li J, Uversky VN, Fink AL, Di Monte DA. 2002. The herbicide paraquat causes up-regulation and aggregation of alpha-synuclein in mice: Paraquat and alpha-synuclein. J Biol Chem. 277(3):1641-1644. https://doi.org/10.1074/jbc.C100560200

Manning-Bog AB, McCormack AL, Purisai MG, Bolin LM, Di Monte DA. 2003. Alpha-synuclein overexpression protects against paraquat-induced neurodegeneration. J Neurosci. 23(8):3095-3099.

Martin CA, Barajas A, Lawless G, Lawal HO, Assani K, Lumintang YP, Nunez V, Krantz DE. 2014. Synergistic effects on dopamine cell death in a Drosophila model of chronic toxin exposure. Neurotoxicology. 44:344-351. https://doi.org/10.1016/j.neuro.2014.08.005

Martinez-Perez DA, Jimenez-Del-Rio M, Velez-Pardo C. 2018. Epigallocatechin-3-gallate protects and prevents paraquat-induced oxidative stress and neurodegeneration in knockdown DJ-1-beta Drosophila melanogaster. Neurotox Res. 34(3):401-416. https://doi.org/10.1007/s12640-018-9899-x

McCormack AL, Atienza JG, Johnston LC, Andersen JK, Vu S, Di Monte DA. 2005. Role of oxidative stress in paraquat-induced dopaminergic cell degeneration. J Neurochem. 93(4):1030-1037. https://doi.org/10.1111/j.1471-4159.2005.03088.x

McCormack AL, Atienza JG, Langston JW, Di Monte DA. 2006. Decreased susceptibility to oxidative stress underlies the resistance of specific dopaminergic cell populations to paraquat-induced degeneration. Neuroscience. 141(2):929-937. https://doi.org/10.1016/j.neuroscience.2006.03.069

McCormack AL, Di Monte DA. 2003. Effects of L-dopa and other amino acids against paraquat-induced nigrostriatal degeneration. J Neurochem. 85(1):82-86. https://doi.org/10.1046/j.1471-4159.2003.01621.x

McCormack AL, Thiruchelvam M, Manning-Bog AB, Thiffault C, Langston JW, Cory-Slechta DA, Di Monte DA. 2002. Environmental risk factors and Parkinson's disease: Selective degeneration of nigral dopaminergic neurons caused by the herbicide paraquat. Neurobiol Dis. 10(2):119-127.

Melchiorri D, Del Duca C, Piccirilli S, Trombetta G, Bagetta G, Nistico G. 1998. Intrahippocampal injection of paraquat produces apoptotic cell death which is prevented by the lazaroid U74389G, in rats. Life Sci. 62(21):1927-1932. https://doi.org/10.1016/s0024-3205(98)00161-1

Menzies FM, Yenisetti SC, Min KT. 2005. Roles of Drosophila DJ-1 in survival of dopaminergic neurons and oxidative stress. Curr Biol. 15(17):1578-1582. https://doi.org/10.1016/j.cub.2005.07.036

Meulener M, Whitworth AJ, Armstrong-Gold CE, Rizzu P, Heutink P, Wes PD, Pallanck LJ, Bonini NM. 2005. Drosophila DJ-1 mutants are selectively sensitive to environmental toxins associated with Parkinson's disease. Curr Biol. 15(17):1572-1577. https://doi.org/10.1016/j.cub.2005.07.064

Minnema DJ, Travis KZ, Breckenridge CB, Sturgess NC, Butt M, Wolf JC, Zadory D, Beck MJ, Mathews JM, Tisdel MO et al. 2014. Dietary administration of paraquat for 13 weeks does not result in a loss of dopaminergic neurons in the substantia nigra of C57BL/6J mice. Regul Toxicol Pharm. 68(2):250-258. https://doi.org/10.1016/j.yrtph.2013.12.010

Miranda-Contreras L, Davila-Ovalles R, Benitez-Diaz P, Pena-Contreras Z, Palacios-Pru E. 2005. Effects of prenatal paraquat and mancozeb exposure on amino acid synaptic transmission in developing mouse cerebellar cortex. Brain Res Dev Brain Res. 160(1):19-27. https://doi.org/10.1016/j.devbrainres.2005.08.001

Mitra S, Chakrabarti N, Bhattacharyya A. 2011. Differential regional expression patterns of alpha-synuclein, TNF-alpha, and IL-1beta; and variable status of dopaminergic neurotoxicity in mouse brain after Paraquat treatment. J Neuroinflammation. 8:163. https://doi.org/10.1186/1742-2094-8-163

Mollace V, Iannone M, Muscoli C, Palma E, Granato T, Rispoli V, Nistico R, Rotiroti D, Salvemini D. 2003. The role of oxidative stress in paraquat-induced neurotoxicity in rats: Protection by non peptidyl superoxide dismutase mimetic. Neurosci Lett. 335(3):163-166. https://doi.org/10.1016/s0304-3940(02)01168-0

Müller TE, Nunes ME, Menezes CC, Marins AT, Leitemperger J, Gressler ACL, Carvalho FB, de Freitas CM, Quadros VA, Fachinetto R. 2018. Sodium selenite prevents paraquat-induced neurotoxicity in zebrafish. Mol Neurobiol. 55(3):1928-1941.

Naudet N, Antier E, Gaillard D, Morignat E, Lakhdar L, Baron T, Bencsik A. 2017. Oral exposure to paraquat triggers earlier expression of phosphorylated alpha-synuclein in the enteric nervous system of A53T mutant human alpha-synuclein transgenic mice. J Neuropathol Exp Neurol. 76(12):1046-1057. https://doi.org/10.1093/jnen/nlx092

Navarro JA, Hessner S, Yenisetti SC, Bayersdorfer F, Zhang L, Voigt A, Schneuwly S, Botella JA. 2014. Analysis of dopaminergic neuronal dysfunction in genetic and toxin-induced models of Parkinson's disease in Drosophila. J Neurochem. 131(3):369-382. https://doi.org/10.1111/jnc.12818

Navarro-Yepes J, Anandhan A, Bradley E, Bohovych I, Yarabe B, de Jong A, Ovaa H, Zhou Y, Khalimonchuk O, Quintanilla-Vega B et al. 2016. Inhibition of protein ubiquitination by paraquat and 1-methyl-4-phenylpyridinium impairs ubiquitin-dependent protein degradation pathways. Mol Neurobiol. 53(8):5229-5251. https://doi.org/10.1007/s12035-015-9414-9

Nellore J, Nandita P. 2015. Paraquat exposure induces behavioral deficits in larval zebrafish during the window of dopamine neurogenesis. Toxicol Rep. 2:950-956.

Nellore J, Shajan A, Antony D, Cynthia PP, Karthick RNS. 2015. Proteinaceous compounds from fragaria ananassa fruit attenuates paraquat induced Parkinson like locomotor and mitochondrial alterations in Zebrafish. Int J Pharm Pharm Sci. 7:246-251.

Niveditha S, Ramesh SR, Shivanandappa T. 2017. Paraquat-induced movement disorder in relation to oxidative stress-mediated neurodegeneration in the brain of Drosophila melanogaster. Neurochem Res. 42(11):3310-3320. https://doi.org/10.1007/s11064-017-2373-y

Nixon AM, Meadowcroft MD, Neely EB, Snyder AM, Purnell CJ, Wright J, Lamendella R, Nandar W, Huang X, Connor JR. 2018. HFE genotype restricts the response to paraquat in a mouse model of neurotoxicity. J Neurochem. 145(4):299-311. https://doi.org/10.1111/jnc.14299

Norris EH, Uryu K, Leight S, Giasson BI, Trojanowski JQ, Lee VM. 2007. Pesticide exposure exacerbates alpha-synucleinopathy in an A53T transgenic mouse model. Am J Pathol. 170(2):658-666. https://doi.org/10.2353/ajpath.2007.060359

Nuber S, Tadros D, Fields J, Overk CR, Ettle B, Kosberg K, Mante M, Rockenstein E, Trejo M, Masliah E. 2014. Environmental neurotoxic challenge of conditional alpha-synuclein transgenic mice predicts a dopaminergic olfactory-striatal interplay in early PD. Acta Neuropathol. 127(4):477-494. https://doi.org/10.1007/s00401-014-1255-5

Nunes ME, Müller TE, Braga MM, Fontana BD, Quadros VA, Marins A, Rodrigues C, Menezes C, Rosemberg DB, Loro VL. 2017. Chronic treatment with paraquat induces brain injury, changes in antioxidant defenses system, and modulates behavioral functions in zebrafish. Mol Neurobiol. 54(6):3925-3934. https://doi.org/10.1007/s12035-016-9919-x

Oeda T, Shimohama S, Kitagawa N, Kohno R, Imura T, Shibasaki H, Ishii N. 2001. Oxidative stress causes abnormal accumulation of familial amyotrophic lateral sclerosis-related mutant SOD1 in transgenic Caenorhabditis elegans. Hum Mol Genet. 10(19):2013-2023. https://doi.org/10.1093/hmg/10.19.2013

Offenburger SL, Ho XY, Tachie-Menson T, Coakley S, Hilliard MA, Gartner A. 2018. 6-OHDA-induced dopaminergic neurodegeneration in Caenorhabditis elegans is promoted by the engulfment pathway and inhibited by the transthyretin-related protein TTR-33. PLoS Genet. 14(1):e1007125. https://doi.org/10.1371/journal.pgen.1007125

Offenburger SL, Jongsma E, Gartner A. 2018. Mutations in Caenorhabditis elegans neuroligin-like glit-1, the apoptosis pathway and the calcium chaperone crt-1 increase dopaminergic neurodegeneration after 6-OHDA treatment. PLoS Genet. 14(1):e1007106. https://doi.org/10.1371/journal.pgen.1007106

O'Leary KT, Parameswaran N, Johnston LC, McIntosh JM, Di Monte DA, Quik M. 2008. Paraquat exposure reduces nicotinic receptor-evoked dopamine release in monkey striatum. J Pharmacol Exp Ther. 327(1):124-129. https://doi.org/10.1124/jpet.108.141861

Ossowska K, Smialowska M, Kuter K, Wieronska J, Zieba B, Wardas J, Nowak P, Dabrowska J, Bortel A, Biedka I et al. 2006. Degeneration of dopaminergic mesocortical neurons and activation of compensatory processes induced by a long-term paraquat administration in rats: Implications for Parkinson's disease. Neuroscience. 141(4):2155-2165. https://doi.org/10.1016/j.neuroscience.2006.05.039

Ossowska K, Wardas J, Kuter K, Nowak P, Dabrowska J, Bortel A, Labus L, Kwiecinski A, Krygowska-Wajs A, Wolfarth S. 2005. Influence of paraquat on dopaminergic transporter in the rat brain. Pharmacol Rep. 57(3):330-335.

Ossowska K, Wardas J, Smialowska M, Kuter K, Lenda T, Wieronska JM, Zieba B, Nowak P, Dabrowska J, Bortel A et al. 2005. A slowly developing dysfunction of dopaminergic nigrostriatal neurons induced by long-term paraquat administration in rats: An animal model of preclinical stages of Parkinson's disease? Eur J Neurosci. 22(6):1294-1304. https://doi.org/10.1111/j.1460-9568.2005.04301.x

Pangestiningsih TW, Wendo WD, Selan YN, Amalo FA, Ndaong NA, Lenda V. 2014. Histological features of Catecholaminergic neuron in substantia nigra induced by paraquat dichloride (1, 1-dimethyl-4, 4 bipyridinium) in wistar rat as a model of Parkinson disease. Indones J Biotechnol. 19(1):91-98.

Patel S, Singh V, Kumar A, Gupta YK, Singh MP. 2006. Status of antioxidant defense system and expression of toxicant responsive genes in striatum of maneb- and paraquat-induced Parkinson's disease phenotype in mouse: Mechanism of neurodegeneration. Brain Res. 1081(1):9-18. https://doi.org/10.1016/j.brainres.2006.01.060

Pattarini R, Rong Y, Shepherd KR, Jiao Y, Qu C, Smeyne RJ, Morgan JI. 2012. Long-lasting transcriptional refractoriness triggered by a single exposure to 1-methyl-4-phenyl-1,2,3,6-tetrahydropyrimidine. Neuroscience. 214:84-105. https://doi.org/10.1016/j.neuroscience.2012.03.047

Peled-Kamar M, Lotem J, Wirguin I, Weiner L, Hermalin A, Groner Y. 1997. Oxidative stress mediates impairment of muscle function in transgenic mice with elevated level of wild-type Cu/Zn superoxide dismutase. Proc Natl Acad Sci U S A. 94(8):3883-3887. https://doi.org/10.1073/pnas.94.8.3883

Peng J, Mao XO, Stevenson FF, Hsu M, Andersen JK. 2004. The herbicide paraquat induces dopaminergic nigral apoptosis through sustained activation of the JNK pathway. J Biol Chem. 279(31):32626-32632. https://doi.org/10.1074/jbc.M404596200

Peng J, Oo ML, Andersen JK. 2010. Synergistic effects of environmental risk factors and gene mutations in Parkinson's disease accelerate age-related neurodegeneration. J Neurochem. 115(6):1363-1373. https://doi.org/10.1111/j.1471-4159.2010.07036.x

Peng J, Peng L, Stevenson FF, Doctrow SR, Andersen JK. 2007. Iron and paraquat as synergistic environmental risk factors in sporadic Parkinson's disease accelerate age-related neurodegeneration. J Neurosci. 27(26):6914-6922. https://doi.org/10.1523/jneurosci.1569-07.2007

Peng J, Stevenson FF, Oo ML, Andersen JK. 2009. Iron-enhanced paraquat-mediated dopaminergic cell death due to increased oxidative stress as a consequence of microglial activation. Free Radic Biol Med. 46(2):312-320. https://doi.org/10.1016/j.freeradbiomed.2008.10.045

Perry TL, Yong VW, Wall RA, Jones K. 1986. Paraquat and two endogenous analogues of the neurotoxic substance N-methyl-4-phenyl-1,2,3,6-tetrahydropyridine do not damage dopaminergic nigrostriatal neurons in the mouse. Neurosci Lett. 69(3):285-289. https://doi.org/10.1016/0304-3940(86)90495-7

Pesah Y, Pham T, Burgess H, Middlebrooks B, Verstreken P, Zhou Y, Harding M, Bellen H, Mardon G. 2004. Drosophila parkin mutants have decreased mass and cell size and increased sensitivity to oxygen radical stress. Development. 131(9):2183-2194. https://doi.org/10.1242/dev.01095

Phom L, Achumi B, Alone DP, Muralidhara, Yenisetti SC. 2014. Curcumin's neuroprotective efficacy in Drosophila model of idiopathic Parkinson's disease is phase specific: Implication of its therapeutic effectiveness. Rejuvenation Res. 17(6):481-489. https://doi.org/10.1089/rej.2014.1591

Pomatto LCD, Carney C, Shen B, Wong S, Halaszynski K, Salomon MP, Davies KJA, Tower J. 2017. The mitochondrial lon protease is required for age-specific and sex-specific adaptation to oxidative stress. Curr Biol. 27(1):1-15. https://doi.org/10.1016/j.cub.2016.10.044

Prasad K, Tarasewicz E, Mathew J, Strickland PA, Buckley B, Richardson JR, Richfield EK. 2009. Toxicokinetics and toxicodynamics of paraquat accumulation in mouse brain. Exp Neurol. 215(2):358-367. https://doi.org/10.1016/j.expneurol.2008.11.003

Prasad K, Winnik B, Thiruchelvam MJ, Buckley B, Mirochnitchenko O, Richfield EK. 2007. Prolonged toxicokinetics and toxicodynamics of paraquat in mouse brain. Environ Health Perspect. 115(10):1448-1453. https://doi.org/10.1289/ehp.9932

Purisai MG, McCormack AL, Cumine S, Li J, Isla MZ, Di Monte DA. 2007. Microglial activation as a priming event leading to paraquat-induced dopaminergic cell degeneration. Neurobiol Dis. 25(2):392-400. https://doi.org/10.1016/j.nbd.2006.10.008

Quintero-Espinosa D, Jimenez-Del-Rio M, Velez-Pardo C. 2017. Knockdown transgenic Lrrk Drosophila resists paraquat-induced locomotor impairment and neurodegeneration: A therapeutic strategy for Parkinson's disease. Brain Res. 1657:253-261. https://doi.org/10.1016/j.brainres.2016.12.023

Rappold PM, Cui M, Chesser AS, Tibbett J, Grima JC, Duan L, Sen N, Javitch JA, Tieu K. 2011. Paraquat neurotoxicity is mediated by the dopamine transporter and organic cation transporter-3. Proc Natl Acad Sci U S A. 108(51):20766-20771. https://doi.org/10.1073/pnas.1115141108

Reeves R, Thiruchelvam M, Baggs RB, Cory-Slechta DA. 2003. Interactions of paraquat and triadimefon: Behavioral and neurochemical effects. Neurotoxicology. 24(6):839-850. https://doi.org/10.1016/s0161-813x(03)00057-3

Ren JP, Zhao YW, Sun XJ. 2009. Toxic influence of chronic oral administration of paraquat on nigrostriatal dopaminergic neurons in C57BL/6 mice. Chin Med J. 122(19):2366-2371.

Rizzo M, Ventrice D, Giannetto F, Cirinna S, Santagati NA, Procopio A, Mollace V, Muscoli C. 2017. Antioxidant activity of oleuropein and semisynthetic acetyl-derivatives determined by measuring malondialdehyde in rat brain. J Pharm Pharmacol. 69(11):1502-1512. https://doi.org/10.1111/jphp.12807

Rodriguez-Rocha H, Garcia Garcia A, Zavala-Flores L, Li S, Madayiputhiya N, Franco R. 2012. Glutaredoxin 1 protects dopaminergic cells by increased protein glutathionylation in experimental Parkinson's disease. Antioxid Redox Signal. 17(12):1676-1693. https://doi.org/10.1089/ars.2011.4474

Rojo AI, Cavada C, de Sagarra MR, Cuadrado A. 2007. Chronic inhalation of rotenone or paraquat does not induce Parkinson's disease symptoms in mice or rats. Exp Neurol. 208(1):120-126. https://doi.org/10.1016/j.expneurol.2007.07.022

Rudyk C, Litteljohn D, Syed S, Dwyer Z, Hayley S. 2015. Paraquat and psychological stressor interactions as pertains to Parkinsonian co-morbidity. Neurobiol Stress. 2:85-93. https://doi.org/10.1016/j.ynstr.2015.09.001

Rudyk CA, McNeill J, Prowse N, Dwyer Z, Farmer K, Litteljohn D, Caldwell W, Hayley S. 2017. Age and chronicity of administration dramatically influenced the impact of low dose paraquat exposure on behavior and hypothalamic-pituitary-adrenal activity. Front Aging Neurosci. 9:222. https://doi.org/10.3389/fnagi.2017.00222

S N, Shivanandappa T. 2018. Neuroprotective action of 4-Hydroxyisophthalic acid against paraquat-induced motor impairment involves amelioration of mitochondrial damage and neurodegeneration in Drosophila. Neurotoxicology. 66:160-169. https://doi.org/10.1016/j.neuro.2018.04.006

Saha S, Guillily MD, Ferree A, Lanceta J, Chan D, Ghosh J, Hsu CH, Segal L, Raghavan K, Matsumoto K et al. 2009. LRRK2 modulates vulnerability to mitochondrial dysfunction in Caenorhabditis elegans. J Neurosci. 29(29):9210-9218. https://doi.org/10.1523/jneurosci.2281-09.2009

Samann J, Hegermann J, von Gromoff E, Eimer S, Baumeister R, Schmidt E. 2009. Caenorhabditits elegans LRK-1 and PINK-1 act antagonistically in stress response and neurite outgrowth. J Biol Chem. 284(24):16482-16491. https://doi.org/10.1074/jbc.M808255200

Sanders LH, Paul KC, Howlett EH, Lawal H, Boppana S, Bronstein JM, Ritz B, Greenamyre JT. 2017. Editor's highlight: Base excision repair variants and pesticide exposure increase Parkinson's disease risk. Toxicol Sci. 158(1):188-198. https://doi.org/10.1093/toxsci/kfx086

Satayavivad J, Sirapat W, Thiantanawat A. 1997. Neurological effects of chronic exposure to low doses of paraquat in rats. Res Commun Pharmacol Toxicol. 2:269-282.

Sato N, Fujii K, Yuge O, Morio M. 1992. Changes in lipid-peroxidation levels and lipid-composition in the lungs, livers, kidneys and brains of mice treated with paraquat. J Appl Toxicol. 12(5):365-368. https://doi.org/10.1002/jat.2550120513

Satpute RM, Pawar PP, Puttewar S, Sawale SD, Ambhore PD. 2017. Effect of resveratrol and tetracycline on the subacute paraquat toxicity in mice. Hum Exp Toxicol. 36(12):1303-1314. https://doi.org/10.1177/0960327116688070

Seo J, Singh NN, Ottesen EW, Sivanesan S, Shishimorova M, Singh RN. 2016. Oxidative stress triggers body-wide skipping of multiple exons of the spinal muscular atrophy gene. PLoS One. 11(4):e0154390. https://doi.org/10.1371/journal.pone.0154390

Shepherd KR, Lee ES, Schmued L, Jiao Y, Ali SF, Oriaku ET, Lamango NS, Soliman KF, Charlton CG. 2006. The potentiating effects of 1-methyl-4-phenyl-1,2,3,6-tetrahydropyridine (MPTP) on paraquat-induced neurochemical and behavioral changes in mice. Pharmacol Biochem Behav. 83(3):349-359. https://doi.org/10.1016/j.pbb.2006.02.013

Shimizu K, Matsubara K, Ohtaki K, Fujimaru S, Saito O, Shiono H. 2003. Paraquat induces long-lasting dopamine overflow through the excitotoxic pathway in the striatum of freely moving rats. Brain Res. 976(2):243-252. https://doi.org/10.1016/s0006-8993(03)02750-1

Shimizu K, Ohtaki K, Matsubara K, Aoyama K, Uezono T, Saito O, Suno M, Ogawa K, Hayase N, Kimura K et al. 2001. Carrier-mediated processes in blood--brain barrier penetration and neural uptake of paraquat. Brain Res. 906(1-2):135-142. https://doi.org/10.1016/s0006-8993(01)02577-x

Shukla AK, Pragya P, Chaouhan HS, Patel DK, Abdin MZ, Kar Chowdhuri D. 2014. Mutation in Drosophila methuselah resists paraquat induced Parkinson-like phenotypes. Neurobiol Aging. 35(10):2419.e2411-2419.e2416. https://doi.org/10.1016/j.neurobiolaging.2014.04.008

Shukla AK, Pragya P, Chaouhan HS, Tiwari AK, Patel DK, Abdin MZ, Chowdhuri DK. 2014. Heat shock protein-70 (Hsp-70) suppresses paraquat-induced neurodegeneration by inhibiting JNK and caspase-3 activation in Drosophila model of Parkinson's disease. PLoS One. 9(6):e98886. https://doi.org/10.1371/journal.pone.0098886

Sidlauskaite E, Gibson JW, Megson IL, Whitfield PD, Tovmasyan A, Batinic-Haberle I, Murphy MP, Moult PR, Cobley JN. 2018. Mitochondrial ROS cause motor deficits induced by synaptic inactivity: Implications for synapse pruning. Redox Biol. 16:344-351. https://doi.org/10.1016/j.redox.2018.03.012

Singh S, Dimri U, Kataria M, Kumari P. 2011. Ameliorative activity of Withania somnifera root extract on paraquat-induced oxidative stress in mice. J Pharmacol Toxicol. 6(4):433-439.

Soares JJ, Rodrigues DT, Goncalves MB, Lemos MC, Gallarreta MS, Bianchini MC, Gayer MC, Puntel RL, Roehrs R, Denardin ELG. 2017. Paraquat exposure-induced Parkinson's disease-like symptoms and oxidative stress in Drosophila melanogaster: Neuroprotective effect of Bougainvillea glabra Choisy. Biomed Pharmacother. 95:245-251. https://doi.org/10.1016/j.biopha.2017.08.073

Somayajulu-Nitu M, Sandhu JK, Cohen J, Sikorska M, Sridhar TS, Matei A, Borowy-Borowski H, Pandey S. 2009. Paraquat induces oxidative stress, neuronal loss in substantia nigra region and parkinsonism in adult rats: Neuroprotection and amelioration of symptoms by water-soluble formulation of coenzyme Q10. BMC Neurosci. 10:88. https://doi.org/10.1186/1471-2202-10-88

Song L, He Y, Ou J, Zhao Y, Li R, Cheng J, Lin CH, Ho MS. 2017. Auxilin underlies progressive locomotor deficits and dopaminergic neuron loss in a Drosophila model of Parkinson's disease. Cell Rep. 18(5):1132-1143. https://doi.org/10.1016/j.celrep.2017.01.005

Songin M, Ossowska K, Kuter K, Strosznajder JB. 2011. Alteration of GSK-3beta in the hippocampus and other brain structures after chronic paraquat administration in rats. Folia Neuropathol. 49(4):319-327.

Songin M, Strosznajder JB, Fital M, Kuter K, Kolasiewicz W, Nowak P, Ossowska K. 2011. Glycogen synthase kinase 3beta and its phosphorylated form (Y216) in the paraquat-induced model of Parkinsonism. Neurotox Res. 19(1):162-171. https://doi.org/10.1007/s12640-010-9153-7

Soylemezoglu T. 2001. The effectiveness of n-acetylcysteine and cinnarizine on paraquat-induced neuro and hepato-toxicity in mice. J Fac Phann Gazi. 18(1):49-57.

Srivastava G, Dixit A, Yadav S, Patel DK, Prakash O, Singh MP. 2012. Resveratrol potentiates cytochrome P450 2 d22-mediated neuroprotection in maneb- and paraquat-induced parkinsonism in the mouse. Free Radic Biol Med. 52(8):1294-1306. https://doi.org/10.1016/j.freeradbiomed.2012.02.005

Su C, Niu P. 2015. Low doses of single or combined agrichemicals induces alpha-synuclein aggregation in nigrostriatal system of mice through inhibition of proteasomal and autophagic pathways. Int J Clin Exp Med. 8(11):20508-20515.

Tang SP, Salam SKN, Jaafar H, Gan SH, Muzaimi M, Sulaiman SA. 2017. Tualang honey protects the rat midbrain and lung against repeated paraquat exposure. Oxid Med Cell Longev. https://doi.org/10.1155/2017/4605782

Tawara T, Fukushima T, Hojo N, Isobe A, Shiwaku K, Setogawa T, Yamane Y. 1996. Effects of paraquat on mitochondrial electron transport system and catecholamine contents in rat brain. Arch Toxicol. 70(9):585-589.

Thiruchelvam M, Brockel BJ, Richfield EK, Baggs RB, Cory-Slechta DA. 2000. Potentiated and preferential effects of combined paraquat and maneb on nigrostriatal dopamine systems: Environmental risk factors for Parkinson's disease? Brain Res. 873(2):225-234. https://doi.org/10.1016/s0006-8993(00)02496-3

Thiruchelvam M, McCormack A, Richfield EK, Baggs RB, Tank AW, Di Monte DA, Cory-Slechta DA. 2003. Age-related irreversible progressive nigrostriatal dopaminergic neurotoxicity in the paraquat and maneb model of the Parkinson's disease phenotype. Eur J Neurosci. 18(3):589-600.

Thiruchelvam M, Richfield EK, Baggs RB, Tank AW, Cory-Slechta DA. 2000. The nigrostriatal dopaminergic system as a preferential target of repeated exposures to combined paraquat and maneb: Implications for Parkinson's disease. J Neurosci. 20(24):9207-9214.

Thiruchelvam M, Richfield EK, Goodman BM, Baggs RB, Cory-Slechta DA. 2002. Developmental exposure to the pesticides paraquat and maneb and the Parkinson's disease phenotype. Neurotoxicology. 23(4-5):621-633.

Ved R, Saha S, Westlund B, Perier C, Burnam L, Sluder A, Hoener M, Rodrigues CM, Alfonso A, Steer C et al. 2005. Similar patterns of mitochondrial vulnerability and rescue induced by genetic modification of alpha-synuclein, parkin, and DJ-1 in Caenorhabditis elegans. J Biol Chem. 280(52):42655-42668. https://doi.org/10.1074/jbc.M505910200

Voronkov DN, Khudoerkov RM, Dikalova YV, Sheloukhova LI. 2016. Quantitative evaluation of changes in the striatal astrocyte axons in simulated parkinsonism. Bull Exp Biol Med. 160(4):505-509. https://doi.org/10.1007/s10517-016-3208-6

Wang D, Tang B, Zhao G, Pan Q, Xia K, Bodmer R, Zhang Z. 2008. Dispensable role of Drosophila ortholog of LRRK2 kinase activity in survival of dopaminergic neurons. Mol Neurodegener. 3:3. https://doi.org/10.1186/1750-1326-3-3

Wang L, Yang H, Wang Q, Zhang Q, Wang Z, Zhang Q, Wu S, Li H. 2018. Paraquat and MPTP induce alteration in the expression profile of long noncoding RNAs in the substantia nigra of mice: Role of the transcription factor Nrf2. Toxicol Lett. 291:11-28. https://doi.org/10.1016/j.toxlet.2018.04.002

Wang Q, Liu S, Hu D, Wang Z, Wang L, Wu T, Wu Z, Mohan C, Peng A. 2016. Identification of apoptosis and macrophage migration events in paraquat-induced oxidative stress using a zebrafish model. Life Sci. 157:116-124. https://doi.org/10.1016/j.lfs.2016.06.009

Wang Q, Ren N, Cai Z, Lin Q, Wang Z, Zhang Q, Wu S, Li H. 2017. Paraquat and MPTP induce neurodegeneration and alteration in the expression profile of microRNAs: The role of transcription factor Nrf2. NPJ Parkinson’s Dis. 3:31. https://doi.org/10.1038/s41531-017-0033-1

Wang R, Zhao X, Xu J, Wen Y, Li A, Lu M, Zhou J. 2018. Astrocytic JWA deletion exacerbates dopaminergic neurodegeneration by decreasing glutamate transporters in mice. Cell Death Dis. 9(3):352. https://doi.org/10.1038/s41419-018-0381-8

Wang XH, Souders CL, 2nd, Zhao YH, Martyniuk CJ. 2018. Paraquat affects mitochondrial bioenergetics, dopamine system expression, and locomotor activity in zebrafish (Danio rerio). Chemosphere. 191:106-117. https://doi.org/10.1016/j.chemosphere.2017.10.032

Watson MB, Nobuta H, Abad C, Lee SK, Bala N, Zhu C, Richter F, Chesselet MF, Waschek JA. 2013. PACAP deficiency sensitizes nigrostriatal dopaminergic neurons to paraquat-induced damage and modulates central and peripheral inflammatory activation in mice. Neuroscience. 240:277-286. https://doi.org/10.1016/j.neuroscience.2013.03.002

Widdowson PS, Farnworth MJ, Upton R, Simpson MG. 1996. No changes in behaviour, nigro-striatal system neurochemistry or neuronal cell death following toxic multiple oral paraquat administration to rats. Hum Exp Toxicol. 15(7):583-591. https://doi.org/10.1177/096032719601500706

Wills J, Credle J, Oaks AW, Duka V, Lee JH, Jones J, Sidhu A. 2012. Paraquat, but not maneb, induces synucleinopathy and tauopathy in striata of mice through inhibition of proteasomal and autophagic pathways. PLoS One. 7(1):e30745. https://doi.org/10.1371/journal.pone.0030745

Woolley DE, Gietzen DW, Gee SJ, Magdalou J, Hammock BD. 1989. Does paraquat (PQ) mimic MPP+ toxicity? Proc West Pharmacol Soc. 32:191-193.

Wu B, Song B, Yang H, Huang B, Chi B, Guo Y, Liu H. 2013. Central nervous system damage due to acute paraquat poisoning: An experimental study with rat model. Neurotoxicology. 35:62-70. https://doi.org/10.1016/j.neuro.2012.12.001

Yadav SK, Prakash J, Chouhan S, Singh SP. 2013. Mucuna pruriens seed extract reduces oxidative stress in nigrostriatal tissue and improves neurobehavioral activity in paraquat-induced Parkinsonian mouse model. Neurochem Int. 62(8):1039-1047. https://doi.org/10.1016/j.neuint.2013.03.015

Yadav SK, Rai SN, Singh SP. 2017. Mucuna pruriens reduces inducible nitric oxide synthase expression in Parkinsonian mice model. J Chem Neuroanat. 80:1-10. https://doi.org/10.1016/j.jchemneu.2016.11.009

Yang W, Chen L, Ding Y, Zhuang X, Kang UJ. 2007. Paraquat induces dopaminergic dysfunction and proteasome impairment in DJ-1-deficient mice. Hum Mol Genet. 16(23):2900-2910. https://doi.org/10.1093/hmg/ddm249

Yin L, Lu L, Prasad K, Richfield EK, Unger EL, Xu J, Jones BC. 2011. Genetic-based, differential susceptibility to paraquat neurotoxicity in mice. Neurotoxicol Teratol. 33(3):415-421. https://doi.org/10.1016/j.ntt.2011.02.012

Zega G, Candiani S, Groppelli S, De Bernardi F, Pennati R. 2010. Neurotoxic effect of the herbicide paraquat on ascidian larvae. Environ Toxicol Pharmacol. 29(1):24-31. https://doi.org/10.1016/j.etap.2009.09.001

Zeitoun-Ghandour S, Leszczyszyn OI, Blindauer CA, Geier FM, Bundy JG, Sturzenbaum SR. 2011. C. elegans metallothioneins: Response to and defence against ROS toxicity. Mol Biosyst. 7(8):2397-2406. https://doi.org/10.1039/c1mb05114h

Zhao F, Wang W, Wang C, Siedlak SL, Fujioka H, Tang B, Zhu X. 2017. Mfn2 protects dopaminergic neurons exposed to paraquat both in vitro and in vivo: Implications for idiopathic Parkinson's disease. Biochim Biophys Acta Mol Basis Dis. 1863(6):1359-1370. https://doi.org/10.1016/j.bbadis.2017.02.016

Zhou H, Huang C, Tong J, Xia XG. 2011. Early exposure to paraquat sensitizes dopaminergic neurons to subsequent silencing of PINK1 gene expression in mice. Int J Biol Sci. 7(8):1180-1187. https://doi.org/10.7150/ijbs.7.1180

## E.5 In Vitro Studies

Certain studies in this list are also included in the Human Studies: Primary Endpoints list, the Animal Studies: Primary Endpoints list, and the Animal Studies: Secondary Endpoints list if they contained data relating to those endpoints in addition to in vitro endpoints.

Aiuchi T, Shirane Y, Kinemuchi H, Arai Y, Kim SK, Nakaya K, Nakamura Y. 1990. Effect of the tetraphenylboron ion on the inhibition of mitochondrial respiration in synaptosomes by the 1-methyl-4-phenylpyridinium ion (MPP(+)). Neurochem Int. 17(1):59-65.

Alural B, Ozerdem A, Allmer J, Genc K, Genc S. 2015. Lithium protects against paraquat neurotoxicity by NRF2 activation and miR-34a inhibition in SH-SY5Y cells. Front Cell Neurosci. 9:209. https://doi.org/10.3389/fncel.2015.00209

An JJ, Lee YP, Kim SY, Lee SH, Kim DW, Lee MJ, Jeong MS, Jang SH, Kang JH, Kwon HY et al. 2008. Transduction of familial amyotrophic lateral sclerosis-related mutant PEP-1-SOD proteins into neuronal cells. Mol Cells. 25(1):55-63.

Anandhan A, Lei S, Levytskyy R, Pappa A, Panayiotidis MI, Cerny RL, Khalimonchuk O, Powers R, Franco R. 2017. Glucose metabolism and AMPK signaling regulate dopaminergic cell death induced by gene (alpha-synuclein)-environment (paraquat) interactions. Mol Neurobiol. 54(5):3825-3842. https://doi.org/10.1007/s12035-016-9906-2

Bajo-Graneras R, Ganfornina MD, Martin-Tejedor E, Sanchez D. 2011. Apolipoprotein D mediates autocrine protection of astrocytes and controls their reactivity level, contributing to the functional maintenance of paraquat-challenged dopaminergic systems. Glia. 59(10):1551-1566. https://doi.org/10.1002/glia.21200

Barlow BK, Lee DW, Cory-Slechta DA, Opanashuk LA. 2005. Modulation of antioxidant defense systems by the environmental pesticide maneb in dopaminergic cells. Neurotoxicology. 26(1):63-75. https://doi.org/10.1016/j.neuro.2004.07.004

Barlow BK, Thiruchelvam MJ, Bennice L, Cory-Slechta DA, Ballatori N, Richfield EK. 2003. Increased synaptosomal dopamine content and brain concentration of paraquat produced by selective dithiocarbamates. J Neurochem. 85(4):1075-1086. https://doi.org/10.1046/j.1471-4159.2003.01773.x

Bonneh-Barkay D, Langston WJ, Di Monte DA. 2005. Toxicity of redox cycling pesticides in primary mesencephalic cultures. Antioxid Redox Signal. 7(5-6):649-653. https://doi.org/10.1089/ars.2005.7.649

Bonneh-Barkay D, Reaney SH, Langston WJ, Di Monte DA. 2005. Redox cycling of the herbicide paraquat in microglial cultures. Brain Res Mol Brain Res. 134(1):52-56. https://doi.org/10.1016/j.molbrainres.2004.11.005

Cantu D, Fulton RE, Drechsel DA, Patel M. 2011. Mitochondrial aconitase knockdown attenuates paraquat-induced dopaminergic cell death via decreased cellular metabolism and release of iron and H(2)O(2). J Neurochem. 118(1):79-92. https://doi.org/10.1111/j.1471-4159.2011.07290.x

Cantu D, Schaack J, Patel M. 2009. Oxidative inactivation of mitochondrial aconitase results in iron and H2O2-mediated neurotoxicity in rat primary mesencephalic cultures. PLoS One. 4(9):e7095. https://doi.org/10.1371/journal.pone.0007095

Caputi FF, Carretta D, Lattanzio F, Palmisano M, Candeletti S, Romualdi P. 2015. Proteasome subunit and opioid receptor gene expression down-regulation induced by paraquat and maneb in human neuroblastoma SH-SY5Y cells. Environ Toxicol Pharmacol. 40(3):895-900. https://doi.org/10.1016/j.etap.2015.09.019

Carroll CB, Zeissler ML, Chadborn N, Gibson K, Williams G, Zajicek JP, Morrison KE, Hanemann CO. 2011. Changes in iron-regulatory gene expression occur in human cell culture models of Parkinson's disease. Neurochem Int. 59(1):73-80. https://doi.org/10.1016/j.neuint.2011.05.006

Carroll CB, Zeissler ML, Hanemann CO, Zajicek JP. 2012. Delta(9)-tetrahydrocannabinol (Delta(9)-THC) exerts a direct neuroprotective effect in a human cell culture model of Parkinson's disease. Neuropathol Appl Neurobiol. 38(6):535-547. https://doi.org/10.1111/j.1365-2990.2011.01248.x

Case AJ, Agraz D, Ahmad IM, Zimmerman MC. 2016. Low-dose Aronia melanocarpa concentrate attenuates paraquat-induced neurotoxicity. Oxid Med Cell Longev. 2016:5296271. https://doi.org/10.1155/2016/5296271

Castello PR, Drechsel DA, Patel M. 2007. Mitochondria are a major source of paraquat-induced reactive oxygen species production in the brain. J Biol Chem. 282(19):14186-14193. https://doi.org/10.1074/jbc.M700827200

Chang X, Lu W, Dou T, Wang X, Lou D, Sun X, Zhou Z. 2013. Paraquat inhibits cell viability via enhanced oxidative stress and apoptosis in human neural progenitor cells. Chem Biol Interact. 206(2):248-255. https://doi.org/10.1016/j.cbi.2013.09.010

Chau KY, Cooper JM, Schapira AH. 2010. Rasagiline protects against alpha-synuclein induced sensitivity to oxidative stress in dopaminergic cells. Neurochem Int. 57(5):525-529. https://doi.org/10.1016/j.neuint.2010.06.017

Chau KY, Korlipara LV, Cooper JM, Schapira AH. 2009. Protection against paraquat and A53T alpha-synuclein toxicity by cabergoline is partially mediated by dopamine receptors. J Neurol Sci. 278(1-2):44-53. https://doi.org/10.1016/j.jns.2008.11.012

Chen AY, Tully T. 2018. A stress-enhanced model for discovery of disease-modifying gene: Ece1-suppresses the toxicity of alpha-synuclein A30P. Neurobiol Dis. 114:153-163. https://doi.org/10.1016/j.nbd.2018.03.003

Chen P, Li A, Zhang M, He M, Chen Z, Wu X, Zhao C, Wang S, Liang L. 2008. Protective effects of a new metalloporphyrin on paraquat-induced oxidative stress and apoptosis in N27 cells. Acta Biochim Biophys Sin (Shanghai). 40(2):125-132. https://doi.org/10.1111/j.1745-7270.2008.00386.x

Chen T, Tan J, Wan Z, Zou Y, Afewerky HK, Zhang Z, Zhang T. 2017. Effects of commonly used pesticides in China on the mitochondria and ubiquitin-proteasome system in Parkinson's disease. Int J Mol Sci. 18(12). https://doi.org/10.3390/ijms18122507

Chen TS, Koutsilieri E, Rausch WD. 1995. MPP+ selectively affects calcium homeostasis in mesencephalic cell cultures from embryonal C57/Bl6 mice. J Neural Transm Gen Sect. 100(2):153-163.

Chen ZH, Yoshida Y, Saito Y, Niki E. 2005. Adaptation to hydrogen peroxide enhances PC12 cell tolerance against oxidative damage. Neurosci Lett. 383(3):256-259. https://doi.org/10.1016/j.neulet.2005.04.022

Chinta SJ, Rane A, Poksay KS, Bredesen DE, Andersen JK, Rao RV. 2008. Coupling endoplasmic reticulum stress to the cell death program in dopaminergic cells: Effect of paraquat. Neuromolecular Med. 10(4):333-342. https://doi.org/10.1007/s12017-008-8047-9

Chinta SJ, Woods G, Demaria M, Rane A, Zou Y, McQuade A, Rajagopalan S, Limbad C, Madden DT, Campisi J et al. 2018. Cellular senescence is induced by the environmental neurotoxin paraquat and contributes to neuropathology linked to Parkinson's disease. Cell Rep. 22(4):930-940. https://doi.org/10.1016/j.celrep.2017.12.092

Choi HS, An JJ, Kim SY, Lee SH, Kim DW, Yoo KY, Won MH, Kang TC, Kwon HJ, Kang JH et al. 2006. PEP-1-SOD fusion protein efficiently protects against paraquat-induced dopaminergic neuron damage in a Parkinson disease mouse model. Free Radic Biol Med. 41(7):1058-1068. https://doi.org/10.1016/j.freeradbiomed.2006.06.006

Choi SH, Kim DW, Kim SY, An JJ, Lee SH, Choi HS, Sohn EJ, Hwang SI, Won MH, Kang TC et al. 2005. Transduced human copper chaperone for Cu,Zn-SOD (PEP-1-CCS) protects against neuronal cell death. Mol Cells. 20(3):401-408.

Choi WS, Abel G, Klintworth H, Flavell RA, Xia Z. 2010. JNK3 mediates paraquat- and rotenone-induced dopaminergic neuron death. J Neuropathol Exp Neurol. 69(5):511-520. https://doi.org/10.1097/NEN.0b013e3181db8100

Choi WS, Kruse SE, Palmiter RD, Xia Z. 2008. Mitochondrial complex I inhibition is not required for dopaminergic neuron death induced by rotenone, MPP+, or paraquat. Proc Natl Acad Sci U S A. 105(39):15136-15141. https://doi.org/10.1073/pnas.0807581105

Chorfa A, Betemps D, Morignat E, Lazizzera C, Hogeveen K, Andrieu T, Baron T. 2013. Specific pesticide-dependent increases in alpha-synuclein levels in human neuroblastoma (SH-SY5Y) and melanoma (SK-MEL-2) cell lines. Toxicol Sci. 133(2):289-297. https://doi.org/10.1093/toxsci/kft076

Chun HS, Gibson GE, DeGiorgio LA, Zhang H, Kidd VJ, Son JH. 2001. Dopaminergic cell death induced by MPP(+), oxidant and specific neurotoxicants shares the common molecular mechanism. J Neurochem. 76(4):1010-1021. https://doi.org/10.1046/j.1471-4159.2001.00096.x

Cicchetti F, Lapointe N, Roberge-Tremblay A, Saint-Pierre M, Jimenez L, Ficke BW, Gross RE. 2005. Systemic exposure to paraquat and maneb models early Parkinson's disease in young adult rats. Neurobiol Dis. 20(2):360-371. https://doi.org/10.1016/j.nbd.2005.03.018

Ciriolo MR, Aquilano K, De Martino A, Carri MT, Rotilio G. 2001. Differential role of superoxide and glutathione in S-nitrosoglutathione-mediated apoptosis: A rationale for mild forms of familial amyotrophic lateral sclerosis associated with less active Cu,Zn superoxide dismutase mutants. J Neurochem. 77(6):1433-1443. https://doi.org/10.1046/j.1471-4159.2001.00383.x

Cosenza M, Bidanset J, Johnson D. 1994. Effects of paraquat on the midbrain micromass cell culture system. In Vitro Toxicol.

Cristovao AC, Barata J, Je G, Kim YS. 2013. PKCdelta mediates paraquat-induced Nox1 expression in dopaminergic neurons. Biochem Biophys Res Commun. 437(3):380-385. https://doi.org/10.1016/j.bbrc.2013.06.085

Cristovao AC, Choi DH, Baltazar G, Beal MF, Kim YS. 2009. The role of NADPH oxidase 1-derived reactive oxygen species in paraquat-mediated dopaminergic cell death. Antioxid Redox Signal. 11(9):2105-2118. https://doi.org/10.1089/ars.2009.2459

Cristovao AC, Guhathakurta S, Bok E, Je G, Yoo SD, Choi DH, Kim YS. 2012. NADPH oxidase 1 mediates alpha-synucleinopathy in Parkinson's disease. J Neurosci. 32(42):14465-14477. https://doi.org/10.1523/jneurosci.2246-12.2012

Crum TS, Gleixner AM, Posimo JM, Mason DM, Broeren MT, Heinemann SD, Wipf P, Brodsky JL, Leak RK. 2015. Heat shock protein responses to aging and proteotoxicity in the olfactory bulb. J Neurochem. 133(6):780-794. https://doi.org/10.1111/jnc.13041

Day BJ, Patel M, Calavetta L, Chang LY, Stamler JS. 1999. A mechanism of paraquat toxicity involving nitric oxide synthase. Proc Natl Acad Sci U S A. 96(22):12760-12765. https://doi.org/10.1073/pnas.96.22.12760

de Oliveira MR, Andrade CMB, Furstenau CR. 2018. Naringenin exerts anti-inflammatory effects in paraquat-treated SH-SY5Y cells through a mechanism associated with the Nrf2/HO-1 axis. Neurochem Res. 43(4):894-903. https://doi.org/10.1007/s11064-018-2495-x

de Oliveira MR, Ferreira GC, Schuck PF. 2016. Protective effect of carnosic acid against paraquat-induced redox impairment and mitochondrial dysfunction in SH-SY5Y cells: Role for PI3K/Akt/Nrf2 pathway. Toxicol In Vitro. 32:41-54. https://doi.org/10.1016/j.tiv.2015.12.005

de Oliveira MR, Peres A, Ferreira GC, Schuck PF, Gama CS, Bosco SMD. 2017. Carnosic acid protects mitochondria of human neuroblastoma SH-SY5Y cells exposed to paraquat through activation of the Nrf2/HO-1axis. Mol Neurobiol. 54(8):5961-5972. https://doi.org/10.1007/s12035-016-0100-3

de Oliveira MR, Peres A, Gama CS, Bosco SMD. 2017. Pinocembrin provides mitochondrial protection by the activation of the Erk1/2-Nrf2 signaling pathway in SH-SY5Y neuroblastoma cells exposed to paraquat. Mol Neurobiol. 54(8):6018-6031. https://doi.org/10.1007/s12035-016-0135-5

de Oliveira MR, Schuck PF, Bosco SMD. 2017. Tanshinone I induces mitochondrial protection through an Nrf2-dependent mechanism in paraquat-treated human neuroblastoma SH-SY5Y cells. Mol Neurobiol. 54(6):4597-4608. https://doi.org/10.1007/s12035-016-0009-x

de Rus Jacquet A, Tambe MA, Ma SY, McCabe GP, Vest JHC, Rochet JC. 2017. Pikuni-Blackfeet traditional medicine: Neuroprotective activities of medicinal plants used to treat Parkinson's disease-related symptoms. J Ethnopharmacol. 206:393-407. https://doi.org/10.1016/j.jep.2017.01.001

Del Pino J, Moyano P, Diaz GG, Anadon MJ, Diaz MJ, Garcia JM, Lobo M, Pelayo A, Sola E, Frejo MT. 2017. Primary hippocampal neuronal cell death induction after acute and repeated paraquat exposures mediated by AChE variants alteration and cholinergic and glutamatergic transmission disruption. Toxicology. 390:88-99. https://doi.org/10.1016/j.tox.2017.09.008

Delic V, Griffin JWD, Zivkovic S, Zhang Y, Phan TA, Gong H, Chaput D, Reynes C, Dinh VB, Cruz J et al. 2017. Individual amino acid supplementation can improve energy metabolism and decrease ROS production in neuronal cells overexpressing alpha-synuclein. Neuromolecular Med. 19(2-3):322-344. https://doi.org/10.1007/s12017-017-8448-8

Ding Q, Keller JN. 2001. Proteasome inhibition in oxidative stress neurotoxicity: Implications for heat shock proteins. J Neurochem. 77(4):1010-1017. https://doi.org/10.1046/j.1471-4159.2001.00302.x

Donaire V, Niso M, Moran JM, Garcia L, Gonzalez-Polo RA, Soler G, Fuentes JM. 2005. Heat shock proteins protect both MPP(+) and paraquat neurotoxicity. Brain Res Bull. 67(6):509-514. https://doi.org/10.1016/j.brainresbull.2005.08.002

Dou T, Yan M, Wang X, Lu W, Zhao L, Lou D, Wu C, Chang X, Zhou Z. 2016. Nrf2/ARE pathway involved in oxidative stress induced by paraquat in human neural progenitor cells. Oxid Med Cell Longev. 2016:8923860. https://doi.org/10.1155/2016/8923860

Dranka BP, Zielonka J, Kanthasamy AG, Kalyanaraman B. 2012. Alterations in bioenergetic function induced by Parkinson's disease mimetic compounds: Lack of correlation with superoxide generation. J Neurochem. 122(5):941-951. https://doi.org/10.1111/j.1471-4159.2012.07836.x

Drechsel DA, Patel M. 2009. Differential contribution of the mitochondrial respiratory chain complexes to reactive oxygen species production by redox cycling agents implicated in parkinsonism. Toxicol Sci. 112(2):427-434. https://doi.org/10.1093/toxsci/kfp223

Drechsel DA, Patel M. 2010. Respiration-dependent H2O2 removal in brain mitochondria via the thioredoxin/peroxiredoxin system. J Biol Chem. 285(36):27850-27858. https://doi.org/10.1074/jbc.M110.101196

Dupiereux I, Falisse-Poirrier N, Zorzi W, Watt NT, Thellin O, Zorzi D, Pierard O, Hooper NM, Heinen E, Elmoualij B. 2008. Protective effect of prion protein via the N-terminal region in mediating a protective effect on paraquat-induced oxidative injury in neuronal cells. J Neurosci Res. 86(3):653-659. https://doi.org/10.1002/jnr.21506

Eiamphungporn W, Yainoy S, Prachayasittikul V. 2015. Angiopep-2-mediated delivery of human manganese superoxide dismutase in brain endothelial cells and its protective effect against oxidative stress. Int J Pept Res Ther. 21(1):63-71. https://doi.org/10.1007/s10989-014-9433-9

Ernst A, Stolzing A, Sandig G, Grune T. 2004. Antioxidants effectively prevent oxidation-induced protein damage in OLN 93 cells. Arch Biochem Biophys. 421(1):54-60. https://doi.org/10.1016/j.abb.2003.10.008

Fei Q, Ethell DW. 2008. Maneb potentiates paraquat neurotoxicity by inducing key Bcl-2 family members. J Neurochem. 105(6):2091-2097. https://doi.org/10.1111/j.1471-4159.2008.05293.x

Fei Q, McCormack AL, Di Monte DA, Ethell DW. 2008. Paraquat neurotoxicity is mediated by a Bak-dependent mechanism. J Biol Chem. 283(6):3357-3364. https://doi.org/10.1074/jbc.M708451200

Feng LR, Maguire-Zeiss KA. 2011. Dopamine and paraquat enhance alpha-synuclein-induced alterations in membrane conductance. Neurotox Res. 20(4):387-401. https://doi.org/10.1007/s12640-011-9255-x

Filograna R, Godena VK, Sanchez-Martinez A, Ferrari E, Casella L, Beltramini M, Bubacco L, Whitworth AJ, Bisaglia M. 2016. Superoxide dismutase (SOD)-mimetic M40403 is protective in cell and fly models of paraquat toxicity: Implications for Parkinson disease. J Biol Chem. 291(17):9257-9267. https://doi.org/10.1074/jbc.M115.708057

Fischer LR, Glass JD. 2010. Oxidative stress induced by loss of Cu,Zn-superoxide dismutase (SOD1) or superoxide-generating herbicides causes axonal degeneration in mouse DRG cultures. Acta Neuropathol. 119(2):249-259. https://doi.org/10.1007/s00401-009-0631-z

Fordel E, Thijs L, Martinet W, Lenjou M, Laufs T, Van Bockstaele D, Moens L, Dewilde S. 2006. Neuroglobin and cytoglobin overexpression protects human SH-SY5Y neuroblastoma cells against oxidative stress-induced cell death. Neurosci Lett. 410(2):146-151. https://doi.org/10.1016/j.neulet.2006.09.027

Frederiksen CM, Clausen J. 1999. The effects of oxidative stress in in vitro cultured astroglial cells. Altern Lab Anim. 27(3):351-357. https://doi.org/10.1177/026119299902700307

Fujimori K, Fukuhara A, Inui T, Allhorn M. 2012. Prevention of paraquat-induced apoptosis in human neuronal SH-SY5Y cells by lipocalin-type prostaglandin D synthase. J Neurochem. 120(2):279-291. https://doi.org/10.1111/j.1471-4159.2011.07570.x

Gabbianelli R, Ferri A, Rotilio G, Carri MT. 1999. Aberrant copper chemistry as a major mediator of oxidative stress in a human cellular model of amyotrophic lateral sclerosis. J Neurochem. 73(3):1175-1180. https://doi.org/10.1046/j.1471-4159.1999.0731175.x

Garcia Garcia A, Anandhan A, Burns M, Chen H, Zhou Y, Franco R. 2013. Impairment of Atg5-dependent autophagic flux promotes paraquat- and MPP(+)-induced apoptosis but not rotenone or 6-hydroxydopamine toxicity. Toxicol Sci. 136(1):166-182. https://doi.org/10.1093/toxsci/kft188

Gegg ME, Cooper JM, Schapira AH, Taanman JW. 2009. Silencing of PINK1 expression affects mitochondrial DNA and oxidative phosphorylation in dopaminergic cells. PLoS One. 4(3):e4756. https://doi.org/10.1371/journal.pone.0004756

Gelinas S, Bureau G, Valastro B, Massicotte G, Cicchetti F, Chiasson K, Gagne B, Blanchet J, Martinoli MG. 2004. Alpha and beta estradiol protect neuronal but not native PC12 cells from paraquat-induced oxidative stress. Neurotox Res. 6(2):141-148.

Geter DR, Kan HL, Lowe ER, Rick DL, Charles GD, Gollapudi BB, Mattsson JL. 2008. Investigations of oxidative stress, antioxidant response, and protein binding in chlorpyrifos exposed rat neuronal PC12 cells. Toxicol Mech Methods. 18(1):17-23. https://doi.org/10.1080/15376510701389530

Ghersi-Egea JF, Livertoux MH, Minn A, Perrin R, Siest G. 1991. Enzyme mediated superoxide radical formation initiated by exogenous molecules in rat brain preparations. Toxicol Appl Pharmacol. 110(1):107-117.

Gomez-Sanchez R, Bravo-San Pedro JM, Niso-Santano M, Soler G, Fuentes JM, Gonzalez-Polo RA. 2010. The neuroprotective effect of talipexole from paraquat-induced cell death in dopaminergic neuronal cells. Neurotoxicology. 31(6):701-708. https://doi.org/10.1016/j.neuro.2010.07.005

Gonzalez-Polo R, Niso-Santano M, Moran JM, Ortiz-Ortiz MA, Bravo-San Pedro JM, Soler G, Fuentes JM. 2009. Silencing DJ-1 reveals its contribution in paraquat-induced autophagy. J Neurochem. 109(3):889-898. https://doi.org/10.1111/j.1471-4159.2009.06020.x

Gonzalez-Polo RA, Niso-Santano M, Ortiz-Ortiz MA, Gomez-Martin A, Moran JM, Garcia-Rubio L, Francisco-Morcillo J, Zaragoza C, Soler G, Fuentes JM. 2007. Inhibition of paraquat-induced autophagy accelerates the apoptotic cell death in neuroblastoma SH-SY5Y cells. Toxicol Sci. 97(2):448-458. https://doi.org/10.1093/toxsci/kfm040

Gonzalez-Polo RA, Rodriguez-Martin A, Moran JM, Niso M, Soler G, Fuentes JM. 2004. Paraquat-induced apoptotic cell death in cerebellar granule cells. Brain Res. 1011(2):170-176. https://doi.org/10.1016/j.brainres.2004.02.078

Gorina R, Sanfeliu C, Galito A, Messeguer A, Planas AM. 2007. Exposure of glia to pro-oxidant agents revealed selective Stat1 activation by H2O2 and Jak2-independent antioxidant features of the Jak2 inhibitor AG490. Glia. 55(13):1313-1324. https://doi.org/10.1002/glia.20542

Grunewald A, Gegg ME, Taanman JW, King RH, Kock N, Klein C, Schapira AH. 2009. Differential effects of PINK1 nonsense and missense mutations on mitochondrial function and morphology. Exp Neurol. 219(1):266-273. https://doi.org/10.1016/j.expneurol.2009.05.027

Grunewald A, Voges L, Rakovic A, Kasten M, Vandebona H, Hemmelmann C, Lohmann K, Orolicki S, Ramirez A, Schapira AH et al. 2010. Mutant Parkin impairs mitochondrial function and morphology in human fibroblasts. PLoS One. 5(9):e12962. https://doi.org/10.1371/journal.pone.0012962

Hara S, Endo T, Kuriiwa F, Kano S. 1991. Different effects of paraquat on microsomal lipid peroxidation in mouse brain, lung and liver. Pharmacol Toxicol. 68(4):260-265.

Hara S, Endo T, Kuriiwa F, Kano S. 1991. Effects of MPTP, MPP+, and paraquat on NADPH-dependent lipid peroxidation in mouse brain and lung microsomes. Biochem Med Metab Biol. 45(3):292-297.

Hara S, Endo T, Kuriiwa F, Kano S. 1991. Interaction between dual NADPH-dependent reactions of paraquat in mouse brain microsomes. Res Commun Chem Pathol Pharmacol. 73(1):119-122.

Hara S, Endo T, Kuriiwa F, Kano S. 1991. Mechanism of paraquat-stimulated lipid peroxidation in mouse brain and pulmonary microsomes. J Pharm Pharmacol. 43(10):731-733. https://doi.org/10.1111/j.2042-7158.1991.tb03468.x

Heinemann SD, Posimo JM, Mason DM, Hutchison DF, Leak RK. 2016. Synergistic stress exacerbation in hippocampal neurons: Evidence favoring the dual-hit hypothesis of neurodegeneration. Hippocampus. 26(8):980-994. https://doi.org/10.1002/hipo.22580

Hirata Y, Sugimura H, Takei H, Nagatsu T. 1986. The effects of pyridinium salts, structurally related compounds of 1-methyl-4-phenylpyridinium ion (MPP+), on tyrosine hydroxylation in rat striatal tissue slices. Brain Res. 397(2):341-344. https://doi.org/10.1016/0006-8993(86)90636-0

Hirayama N, Aki T, Funakoshi T, Noritake K, Unuma K, Uemura K. 2018. Necrosis in human neuronal cells exposed to paraquat. J Toxicol Sci. 43(3):193-202. https://doi.org/10.2131/jts.43.193

Hogberg HT, Kinsner-Ovaskainen A, Hartung T, Coecke S, Bal-Price AK. 2009. Gene expression as a sensitive endpoint to evaluate cell differentiation and maturation of the developing central nervous system in primary cultures of rat cerebellar granule cells (CGCs) exposed to pesticides. Toxicol Appl Pharmacol. 235(3):268-286. https://doi.org/10.1016/j.taap.2008.12.014

Hou RR, Chen JZ, Chen H, Kang XG, Li MG, Wang BR. 2008. Neuroprotective effects of (-)-epigallocatechin-3-gallate (EGCG) on paraquat-induced apoptosis in PC12 cells. Cell Biol Int. 32(1):22-30. https://doi.org/10.1016/j.cellbi.2007.08.007

Huang CL, Chao CC, Lee YC, Lu MK, Cheng JJ, Yang YC, Wang VC, Chang WC, Huang NK. 2016. Paraquat induces cell death through impairing mitochondrial membrane permeability. Mol Neurobiol. 53(4):2169-2188. https://doi.org/10.1007/s12035-015-9198-y

Huang CL, Lee YC, Yang YC, Kuo TY, Huang NK. 2012. Minocycline prevents paraquat-induced cell death through attenuating endoplasmic reticulum stress and mitochondrial dysfunction. Toxicol Lett. 209(3):203-210. https://doi.org/10.1016/j.toxlet.2011.12.021

Huang M, Lou D, Cai Q, Chang X, Wang X, Zhou Z. 2014. Characterization of paraquat-induced miRNA profiling response in hNPCs undergoing proliferation. Int J Mol Sci. 15(10):18422-18436. https://doi.org/10.3390/ijms151018422

Huang M, Lou D, Wang YP, Cai Q, Li HH. 2016. Paraquat inhibited differentiation in human neural progenitor cells (hNPCs) and down regulated miR-200a expression by targeting CTNNB1. Environ Toxicol Pharmacol. 42:205-211. https://doi.org/10.1016/j.etap.2016.01.018

Isaev NK, Stelmashook EV, Ruscher K, Andreeva NA, Zorov DB. 2004. Menadione reduces rotenone-induced cell death in cerebellar granule neurons. Neuroreport. 15(14):2227-2231.

Izumi Y, Ezumi M, Takada-Takatori Y, Akaike A, Kume T. 2014. Endogenous dopamine is involved in the herbicide paraquat-induced dopaminergic cell death. Toxicol Sci. 139(2):466-478. https://doi.org/10.1093/toxsci/kfu054

Izumi Y, Yamamoto N, Matsushima S, Yamamoto T, Takada-Takatori Y, Akaike A, Kume T. 2015. Compensatory role of the Nrf2-ARE pathway against paraquat toxicity: Relevance of 26S proteasome activity. J Pharmacol Sci. 129(3):150-159. https://doi.org/10.1016/j.jphs.2015.09.003

Janda E, Lascala A, Carresi C, Parafati M, Aprigliano S, Russo V, Savoia C, Ziviani E, Musolino V, Morani F et al. 2015. Parkinsonian toxin-induced oxidative stress inhibits basal autophagy in astrocytes via NQO2/quinone oxidoreductase 2: Implications for neuroprotection. Autophagy. 11(7):1063-1080. https://doi.org/10.1080/15548627.2015.1058683

Janda E, Parafati M, Aprigliano S, Carresi C, Visalli V, Sacco I, Ventrice D, Mega T, Vadala N, Rinaldi S et al. 2013. The antidote effect of quinone oxidoreductase 2 inhibitor against paraquat-induced toxicity in vitro and in vivo. Br J Pharmacol. 168(1):46-59. https://doi.org/10.1111/j.1476-5381.2012.01870.x

Jaroonwitchawan T, Chaicharoenaudomrung N, Namkaew J, Noisa P. 2017. Curcumin attenuates paraquat-induced cell death in human neuroblastoma cells through modulating oxidative stress and autophagy. Neurosci Lett. 636:40-47. https://doi.org/10.1016/j.neulet.2016.10.050

Kang D, Miyako K, Kuribayashi F, Hasegawa E, Mitsumoto A, Nagano T, Takeshige K. 1997. Changes of energy metabolism induced by 1-methyl-4-phenylpyridinium (MPP+)-related compounds in rat pheochromocytoma PC12 cells. Arch Biochem Biophys. 337(1):75-80. https://doi.org/10.1006/abbi.1996.9727

Kang X, Chen J, Xu Z, Li H, Wang B. 2007. Protective effects of Ginkgo biloba extract on paraquat-induced apoptosis of PC12 cells. Toxicol In Vitro. 21(6):1003-1009. https://doi.org/10.1016/j.tiv.2007.02.004

Kim DW, Eum WS, Jang SH, Kim SY, Choi HS, Choi SH, An JJ, Lee SH, Lee KS, Han K et al. 2005. Transduced Tat-SOD fusion protein protects against ischemic brain injury. Mol Cells. 19(1):88-96.

Kim S, Hwang J, Lee WH, Hwang DY, Suk K. 2008. Role of protein kinase Cdelta in paraquat-induced glial cell death. J Neurosci Res. 86(9):2062-2070. https://doi.org/10.1002/jnr.21643

Kim SJ, Kim JE, Moon IS. 2004. Paraquat induces apoptosis of cultured rat cortical cells. Mol Cells. 17(1):102-107.

Kim SU, Park YH, Min JS, Sun HN, Han YH, Hua JM, Lee TH, Lee SR, Chang KT, Kang SW et al. 2013. Peroxiredoxin I is a ROS/p38 MAPK-dependent inducible antioxidant that regulates NF-kappaB-mediated iNOS induction and microglial activation. J Neuroimmunol. 259(1-2):26-36. https://doi.org/10.1016/j.jneuroim.2013.03.006

Kind B, Koehler K, Krumbholz M, Landgraf D, Huebner A. 2010. Intracellular ROS level is increased in fibroblasts of triple A syndrome patients. J Mol Med (Berl). 88(12):1233-1242. https://doi.org/10.1007/s00109-010-0661-y

Klintworth H, Garden G, Xia Z. 2009. Rotenone and paraquat do not directly activate microglia or induce inflammatory cytokine release. Neurosci Lett. 462(1):1-5. https://doi.org/10.1016/j.neulet.2009.06.065

Klintworth H, Newhouse K, Li T, Choi WS, Faigle R, Xia Z. 2007. Activation of c-Jun N-terminal protein kinase is a common mechanism underlying paraquat- and rotenone-induced dopaminergic cell apoptosis. Toxicol Sci. 97(1):149-162. https://doi.org/10.1093/toxsci/kfm029

Kong M, Ba M, Liang H, Ma L, Yu Q, Yu T, Wang Y. 2012. 5'-Aza-dC sensitizes paraquat toxic effects on PC12 cell. Neurosci Lett. 524(1):35-39. https://doi.org/10.1016/j.neulet.2012.07.001

Kulkarni A, McNeill D, Gleichmann M, Mattson M, Wilson D, III. 2008. XRCC1 protects against the lethality of induced oxidative DNA damage in nondividing neural cells. Nucleic Acids Res. 36(15):5111-5121. https://doi.org/10.1093/nar/gkn480

Kwon HJ, Heo JY, Shim JH, Park JH, Seo KS, Ryu MJ, Han JS, Shong M, Son JH, Kweon GR. 2011. DJ-1 mediates paraquat-induced dopaminergic neuronal cell death. Toxicol Lett. 202(2):85-92. https://doi.org/10.1016/j.toxlet.2011.01.018

Lam PY, Ko KM. 2011. (-)Schisandrin B ameliorates paraquat-induced oxidative stress by suppressing glutathione depletion and enhancing glutathione recovery in differentiated PC12 cells. BioFactors. 37(1):51-57. https://doi.org/10.1002/biof.136

Lambert CE, Bondy SC. 1989. Effects of MPTP, MPP+ and paraquat on mitochondrial potential and oxidative stress. Life Sci. 44(18):1277-1284. https://doi.org/10.1016/0024-3205(89)90365-2

Lee CY, Lee CH, Shih CC, Liou HH. 2008. Paraquat inhibits postsynaptic AMPA receptors on dopaminergic neurons in the substantia nigra pars compacta. Biochem Pharmacol. 76(9):1155-1164. https://doi.org/10.1016/j.bcp.2008.08.006

Lee HJ, Han J, Jang Y, Kim SJ, Park JH, Seo KS, Jeong S, Shin S, Lim K, Heo JY et al. 2015. Docosahexaenoic acid prevents paraquat-induced reactive oxygen species production in dopaminergic neurons via enhancement of glutathione homeostasis. Biochem Biophys Res Commun. 457(1):95-100. https://doi.org/10.1016/j.bbrc.2014.12.085

Lee J, Kim S, Shin DH, Kim HJ, Lee K. 2011. Neuroprotective effect of Cu,Zn-superoxide dismutase fused to a TCTP-derived protein transduction domain. Eur J Pharmacol. 666(1-3):87-92. https://doi.org/10.1016/j.ejphar.2011.05.040

Lei S, Zavala-Flores L, Garcia Garcia A, Nandakumar R, Huang Y, Madayiputhiya N, Stanton RC, Dodds ED, Powers R, Franco R. 2014. Alterations in energy/redox metabolism induced by mitochondrial and environmental toxins: A specific role for glucose-6-phosphate-dehydrogenase and the pentose phosphate pathway in paraquat toxicity. ACS Chem Biol. 9(9):2032-2048. https://doi.org/10.1021/cb400894a

Lenzken SC, Romeo V, Zolezzi F, Cordero F, Lamorte G, Bonanno D, Biancolini D, Cozzolino M, Pesaresi MG, Maracchioni A et al. 2011. Mutant SOD1 and mitochondrial damage alter expression and splicing of genes controlling neuritogenesis in models of neurodegeneration. Hum Mutat. 32(2):168-182. https://doi.org/10.1002/humu.21394

Lertkaeo P, Limmongkon A, Srikummool M, Boonsong T, Supanpaiboon W, Surangkul D. 2017. Antioxidative and neuroprotective activities of peanut sprout extracts against oxidative stress in SK-N-SH cells. Asian Pac J Trop Biomed. 7(1):64-69.

Li F, Tian X, Zhou Y, Zhu L, Wang B, Ding M, Pang H. 2012. Dysregulated expression of secretogranin III is involved in neurotoxin-induced dopaminergic neuron apoptosis. J Neurosci Res. 90(12):2237-2246. https://doi.org/10.1002/jnr.23121

Li FR, Ge BA, Damirin A. 2017. Overexpression of p58ipk protects neuroblastoma against paraquat-induced toxicity. Int J Clin Exp Pathol. 10(8):8233-8242.

Li H, Wu S, Wang Z, Lin W, Zhang C, Huang B. 2012. Neuroprotective effects of tert-butylhydroquinone on paraquat-induced dopaminergic cell degeneration in C57BL/6 mice and in PC12 cells. Arch Toxicol. 86(11):1729-1740. https://doi.org/10.1007/s00204-012-0935-y

Li K, Cheng X, Jiang J, Wang J, Xie J, Hu X, Huang Y, Song L, Liu M, Cai L et al. 2017. The toxic influence of paraquat on hippocampal neurogenesis in adult mice. Food Chem Toxicol. 106(Pt A):356-366. https://doi.org/10.1016/j.fct.2017.05.067

Li QY, Pedersen C, Day BJ, Patel M. 2001. Dependence of excitotoxic neurodegeneration on mitochondrial aconitase inactivation. J Neurochem. 78(4):746-755. https://doi.org/10.1046/j.1471-4159.2001.00457.x

Li X, Sun AY. 1999. Paraquat induced activation of transcription factor AP-1 and apoptosis in PC12 cells. J Neural Transm (Vienna). 106(1):1-21. https://doi.org/10.1007/s007020050137

Li Z, Dong T, Proschel C, Noble M. 2007. Chemically diverse toxicants converge on Fyn and c-Cbl to disrupt precursor cell function. PLoS Biol. 5(2):e35. https://doi.org/10.1371/journal.pbio.0050035

Li Z, Zheng J, Zhang XF. 2018. Detrimental effects of paraquat on astrocytes-regulating synaptic functions. Dose Response. 16(2):1559325818761681. https://doi.org/10.1177/1559325818761681

Liddell JR, Obando D, Liu J, Ganio G, Volitakis I, Mok SS, Crouch PJ, White AR, Codd R. 2013. Lipophilic adamantyl- or deferasirox-based conjugates of desferrioxamine B have enhanced neuroprotective capacity: Implications for Parkinson disease. Free Radic Biol Med. 60:147-156. https://doi.org/10.1016/j.freeradbiomed.2013.01.027

Liu J, Narasimhan P, Song YS, Nishi T, Yu F, Lee YS, Chan PH. 2006. Epo protects SOD2-deficient mouse astrocytes from damage by oxidative stress. Glia. 53(4):360-365. https://doi.org/10.1002/glia.20289

Loo LS, McNamara JO. 2006. Impaired volume regulation is the mechanism of excitotoxic sensitization to complement. J Neurosci. 26(40):10177-10187. https://doi.org/10.1523/jneurosci.2628-06.2006

Lopert P, Day BJ, Patel M. 2012. Thioredoxin reductase deficiency potentiates oxidative stress, mitochondrial dysfunction and cell death in dopaminergic cells. PLoS One. 7(11):e50683. https://doi.org/10.1371/journal.pone.0050683

Lopert P, Patel M. 2014. Nicotinamide nucleotide transhydrogenase (Nnt) links the substrate requirement in brain mitochondria for hydrogen peroxide removal to the thioredoxin/peroxiredoxin (Trx/Prx) system. J Biol Chem. 289(22):15611-15620. https://doi.org/10.1074/jbc.M113.533653

Luo Y, Henricksen LA, Giuliano RE, Prifti L, Callahan LM, Federoff HJ. 2007. VIP is a transcriptional target of Nurr1 in dopaminergic cells. Exp Neurol. 203(1):221-232. https://doi.org/10.1016/j.expneurol.2006.08.005

Mailloux RJ, Yumvihoze E, Chan HM. 2015. Superoxide produced in the matrix of mitochondria enhances methylmercury toxicity in human neuroblastoma cells. Toxicol Appl Pharmacol. 289(3):371-380. https://doi.org/10.1016/j.taap.2015.11.001

Mak SK, Tewari D, Tetrud JW, Langston JW, Schule B. 2011. Mitochondrial dysfunction in skin fibroblasts from a Parkinson's disease patient with an alpha-synuclein triplication. J Parkinsons Dis. 1(2):175-183. https://doi.org/10.3233/jpd-2011-11025

Mangano EN, Peters S, Litteljohn D, So R, Bethune C, Bobyn J, Clarke M, Hayley S. 2011. Granulocyte macrophage-colony stimulating factor protects against substantia nigra dopaminergic cell loss in an environmental toxin model of Parkinson's disease. Neurobiol Dis. 43(1):99-112. https://doi.org/10.1016/j.nbd.2011.02.011

Manning-Bog AB, McCormack AL, Li J, Uversky VN, Fink AL, Di Monte DA. 2002. The herbicide paraquat causes up-regulation and aggregation of alpha-synuclein in mice: Paraquat and alpha-synuclein. J Biol Chem. 277(3):1641-1644. https://doi.org/10.1074/jbc.C100560200

Manthey D, Gamerdinger M, Behl C. 2010. The selective beta1-adrenoceptor antagonist nebivolol is a potential oestrogen receptor agonist with neuroprotective abilities. Br J Pharmacol. 159(6):1264-1273. https://doi.org/10.1111/j.1476-5381.2009.00610.x

Maracchioni A, Totaro A, Angelini DF, Di Penta A, Bernardi G, Carri MT, Achsel T. 2007. Mitochondrial damage modulates alternative splicing in neuronal cells: Implications for neurodegeneration. J Neurochem. 100(1):142-153. https://doi.org/10.1111/j.1471-4159.2006.04204.x

Margolis AS, Porasuphatana S, Rosen GM. 2000. Role of paraquat in the uncoupling of nitric oxide synthase. Biochim Biophys Acta. 1524(2-3):253-257. https://doi.org/10.1016/s0304-4165(00)00167-7

Martins JB, Bastos Mde L, Carvalho F, Capela JP. 2013. Differential effects of methyl-4-phenylpyridinium ion, rotenone, and paraquat on differentiated SH-SY5Y cells. J Toxicol. 2013:347312. https://doi.org/10.1155/2013/347312

McCarthy S, Somayajulu M, Sikorska M, Borowy-Borowski H, Pandey S. 2004. Paraquat induces oxidative stress and neuronal cell death; neuroprotection by water-soluble Coenzyme Q10. Toxicol Appl Pharmacol. 201(1):21-31. https://doi.org/10.1016/j.taap.2004.04.019

Meyerowitz J, Parker SJ, Vella LJ, Ng D, Price KA, Liddell JR, Caragounis A, Li QX, Masters CL, Nonaka T et al. 2011. C-Jun N-terminal kinase controls TDP-43 accumulation in stress granules induced by oxidative stress. Mol Neurodegener. 6:57. https://doi.org/10.1186/1750-1326-6-57

Miller RL, Sun GY, Sun AY. 2007. Cytotoxicity of paraquat in microglial cells: Involvement of PKCdelta- and ERK1/2-dependent NADPH oxidase. Brain Res. 1167:129-139. https://doi.org/10.1016/j.brainres.2007.06.046

Minelli A, Conte C, Grottelli S, Bellezza I, Cacciatore I, Bolanos JP. 2009. Cyclo(His-Pro) promotes cytoprotection by activating Nrf2-mediated up-regulation of antioxidant defence. J Cell Mol Med. 13(6):1149-1161. https://doi.org/10.1111/j.1582-4934.2008.00326.x

Minelli A, Conte C, Grottelli S, Bellezza I, Emiliani C, Bolanos JP. 2009. Cyclo(His-Pro) up-regulates heme oxygenase 1 via activation of Nrf2-ARE signalling. J Neurochem. 111(4):956-966. https://doi.org/10.1111/j.1471-4159.2009.06376.x

Mizuno K, Kume T, Muto C, Takada-Takatori Y, Izumi Y, Sugimoto H, Akaike A. 2011. Glutathione biosynthesis via activation of the nuclear factor E2-related factor 2 (Nrf2)--antioxidant-response element (ARE) pathway is essential for neuroprotective effects of sulforaphane and 6-(methylsulfinyl) hexyl isothiocyanate. J Pharmacol Sci. 115(3):320-328.

Moran JM, Gonzalez-Polo RA, Ortiz-Ortiz MA, Niso-Santano M, Soler G, Fuentes JM. 2008. Identification of genes associated with paraquat-induced toxicity in SH-SY5Y cells by PCR array focused on apoptotic pathways. J Toxicol Environ Health A. 71(22):1457-1467. https://doi.org/10.1080/15287390802329364

Moran JM, Ortiz-Ortiz MA, Ruiz-Mesa LM, Niso-Santano M, Bravosanpedro JM, Sanchez RG, Gonzalez-Polo RA, Fuentes JM. 2010. Effect of paraquat exposure on nitric oxide-responsive genes in rat mesencephalic cells. Nitric Oxide. 23(1):51-59. https://doi.org/10.1016/j.niox.2010.04.002

Morita K, Tokunaga I, Kubo S. 1999. Cytotoxic effect of paraquat on rat C6 glioma cells: Evidence for the possibility of non-oxidative damage to the cells. Jap J Pharmacol. 79(1):121-124.

Narasimhan M, Riar AK, Rathinam ML, Vedpathak D, Henderson G, Mahimainathan L. 2014. Hydrogen peroxide responsive miR153 targets Nrf2/ARE cytoprotection in paraquat induced dopaminergic neurotoxicity. Toxicol Lett. 228(3):179-191. https://doi.org/10.1016/j.toxlet.2014.05.020

Navarro-Yepes J, Anandhan A, Bradley E, Bohovych I, Yarabe B, de Jong A, Ovaa H, Zhou Y, Khalimonchuk O, Quintanilla-Vega B et al. 2016. Inhibition of protein ubiquitination by paraquat and 1-methyl-4-phenylpyridinium impairs ubiquitin-dependent protein degradation pathways. Mol Neurobiol. 53(8):5229-5251. https://doi.org/10.1007/s12035-015-9414-9

Nga AK-S, Tho L-Y, Lim C-H, Lim C-K, Say Y-H. 2016. Evaluation of neuroprotective properties of two synthetic prenylated xanthone analogues against paraquat and 6-hydroxydopamine toxicity in human neuroblastoma SHSY5Y cells. Trop J Pharm Res. 15(12):2611-2618.

Niso-Santano M, Bravo-San Pedro JM, Gomez-Sanchez R, Climent V, Soler G, Fuentes JM, Gonzalez-Polo RA. 2011. ASK1 overexpression accelerates paraquat-induced autophagy via endoplasmic reticulum stress. Toxicol Sci. 119(1):156-168. https://doi.org/10.1093/toxsci/kfq313

Niso-Santano M, Gonzalez-Polo RA, Bravo-San Pedro JM, Gomez-Sanchez R, Lastres-Becker I, Ortiz-Ortiz MA, Soler G, Moran JM, Cuadrado A, Fuentes JM. 2010. Activation of apoptosis signal-regulating kinase 1 is a key factor in paraquat-induced cell death: Modulation by the Nrf2/Trx axis. Free Radic Biol Med. 48(10):1370-1381. https://doi.org/10.1016/j.freeradbiomed.2010.02.024

Niso-Santano M, Moran JM, Garcia-Rubio L, Gomez-Martin A, Gonzalez-Polo RA, Soler G, Fuentes JM. 2006. Low concentrations of paraquat induces early activation of extracellular signal-regulated kinase 1/2, protein kinase B, and c-Jun N-terminal kinase 1/2 pathways: Role of c-Jun N-terminal kinase in paraquat-induced cell death. Toxicol Sci. 92(2):507-515. https://doi.org/10.1093/toxsci/kfl013

Noack H, Possel H, Rethfeldt C, Keilhoff G, Wolf G. 1999. Peroxynitrite mediated damage and lowered superoxide tolerance in primary cortical glial cultures after induction of the inducible isoform of NOS. Glia. 28(1):13-24.

Olesen BST, Zhang W, Clausen J, Vang O, Hansen PE. 2010. Effect of paraquat and amyloid-beta-peptide on the metabolism in primary astrocytes studied by 1H NMR. Open Mag Res J. 3:1-13.

Olesen BT, Clausen J, Vang O. 2008. Characterization of the transcriptional profile in primary astrocytes after oxidative stress induced by paraquat. Neurotoxicology. 29(1):13-21. https://doi.org/10.1016/j.neuro.2007.08.010

Ortiz-Ortiz MA, Moran JM, Bravosanpedro JM, Gonzalez-Polo RA, Niso-Santano M, Anantharam V, Kanthasamy AG, Soler G, Fuentes JM. 2009. Curcumin enhances paraquat-induced apoptosis of N27 mesencephalic cells via the generation of reactive oxygen species. Neurotoxicology. 30(6):1008-1018. https://doi.org/10.1016/j.neuro.2009.07.016

Ortiz-Ortiz MA, Moran JM, Gonzalez-Polo RA, Niso-Santano M, Soler G, Bravo-San Pedro JM, Fuentes JM. 2009. Nitric oxide-mediated toxicity in paraquat-exposed SH-SY5Y cells: A protective role of 7-nitroindazole. Neurotox Res. 16(2):160-173. https://doi.org/10.1007/s12640-009-9065-6

Ortiz-Ortiz MA, Moran JM, Ruiz-Mesa LM, Bonmatty RG, Fuentes JM. 2011. Protective effect of the glial cell line-derived neurotrophic factor (GDNF) on human mesencephalic neuron-derived cells against neurotoxicity induced by paraquat. Environ Toxicol Pharmacol. 31(1):129-136. https://doi.org/10.1016/j.etap.2010.09.013

Ortiz-Ortiz MA, Moran JM, Ruiz-Mesa LM, Bravo-San Pedro JM, Fuentes JM. 2010. Paraquat exposure induces nuclear translocation of glyceraldehyde-3-phosphate dehydrogenase (GAPDH) and the activation of the nitric oxide-GAPDH-Siah cell death cascade. Toxicol Sci. 116(2):614-622. https://doi.org/10.1093/toxsci/kfq146

Osakada F, Hashino A, Kume T, Katsuki H, Kaneko S, Akaike A. 2003. Neuroprotective effects of alpha-tocopherol on oxidative stress in rat striatal cultures. Eur J Pharmacol. 465(1-2):15-22. https://doi.org/10.1016/s0014-2999(03)01495-x

Osakada F, Hashino A, Kume T, Katsuki H, Kaneko S, Akaike A. 2004. Alpha-tocotrienol provides the most potent neuroprotection among vitamin E analogs on cultured striatal neurons. Neuropharmacology. 47(6):904-915. https://doi.org/10.1016/j.neuropharm.2004.06.029

Osakada F, Kawato Y, Kume T, Katsuki H, Sugimoto H, Akaike A. 2004. Serofendic acid, a sulfur-containing diterpenoid derived from fetal calf serum, attenuates reactive oxygen species-induced oxidative stress in cultured striatal neurons. J Pharmacol Exp Ther. 311(1):51-59. https://doi.org/10.1124/jpet.104.070334

Parker SJ, Meyerowitz J, James JL, Liddell JR, Crouch PJ, Kanninen KM, White AR. 2012. Endogenous TDP-43 localized to stress granules can subsequently form protein aggregates. Neurochem Int. 60(4):415-424. https://doi.org/10.1016/j.neuint.2012.01.019

Parker SJ, Meyerowitz J, James JL, Liddell JR, Nonaka T, Hasegawa M, Kanninen KM, Lim S, Paterson BM, Donnelly PS et al. 2012. Inhibition of TDP-43 accumulation by bis(thiosemicarbazonato)-copper complexes. PLoS One. 7(8):e42277. https://doi.org/10.1371/journal.pone.0042277

Peng J, Mao XO, Stevenson FF, Hsu M, Andersen JK. 2004. The herbicide paraquat induces dopaminergic nigral apoptosis through sustained activation of the JNK pathway. J Biol Chem. 279(31):32626-32632. https://doi.org/10.1074/jbc.M404596200

Peng J, Oo ML, Andersen JK. 2010. Synergistic effects of environmental risk factors and gene mutations in Parkinson's disease accelerate age-related neurodegeneration. J Neurochem. 115(6):1363-1373. https://doi.org/10.1111/j.1471-4159.2010.07036.x

Peng J, Peng L, Stevenson FF, Doctrow SR, Andersen JK. 2007. Iron and paraquat as synergistic environmental risk factors in sporadic Parkinson's disease accelerate age-related neurodegeneration. J Neurosci. 27(26):6914-6922. https://doi.org/10.1523/jneurosci.1569-07.2007

Peng J, Stevenson FF, Doctrow SR, Andersen JK. 2005. Superoxide dismutase/catalase mimetics are neuroprotective against selective paraquat-mediated dopaminergic neuron death in the substantial nigra: Implications for Parkinson disease. J Biol Chem. 280(32):29194-29198. https://doi.org/10.1074/jbc.M500984200

Peng J, Stevenson FF, Oo ML, Andersen JK. 2009. Iron-enhanced paraquat-mediated dopaminergic cell death due to increased oxidative stress as a consequence of microglial activation. Free Radic Biol Med. 46(2):312-320. https://doi.org/10.1016/j.freeradbiomed.2008.10.045

Ramachandiran S, Hansen JM, Jones DP, Richardson JR, Miller GW. 2007. Divergent mechanisms of paraquat, MPP+, and rotenone toxicity: Oxidation of thioredoxin and caspase-3 activation. Toxicol Sci. 95(1):163-171. https://doi.org/10.1093/toxsci/kfl125

Rathinam ML, Watts LT, Narasimhan M, Riar AK, Mahimainathan L, Henderson GI. 2012. Astrocyte mediated protection of fetal cerebral cortical neurons from rotenone and paraquat. Environ Toxicol Pharmacol. 33(2):353-360. https://doi.org/10.1016/j.etap.2011.12.027

Ravi SK, Narasingappa RB, Joshi CG, Girish TK, Vincent B. 2018. Neuroprotective effects of Cassia tora against paraquat-induced neurodegeneration: Relevance for Parkinson's disease. Nat Prod Res. 32(12):1476-1480. https://doi.org/10.1080/14786419.2017.1353504

Rhodes SL, Fitzmaurice AG, Cockburn M, Bronstein JM, Sinsheimer JS, Ritz B. 2013. Pesticides that inhibit the ubiquitin-proteasome system: Effect measure modification by genetic variation in SKP1 in Parkinson's disease. Environ Res. 126:1-8. https://doi.org/10.1016/j.envres.2013.08.001

Richardson JR, Quan Y, Sherer TB, Greenamyre JT, Miller GW. 2005. Paraquat neurotoxicity is distinct from that of MPTP and rotenone. Toxicol Sci. 88(1):193-201. https://doi.org/10.1093/toxsci/kfi304

Robb EL, Stuart JA. 2011. Resveratrol interacts with estrogen receptor-beta to inhibit cell replicative growth and enhance stress resistance by upregulating mitochondrial superoxide dismutase. Free Radic Biol Med. 50(7):821-831. https://doi.org/10.1016/j.freeradbiomed.2010.12.038

Rodriguez-Rocha H, Garcia Garcia A, Zavala-Flores L, Li S, Madayiputhiya N, Franco R. 2012. Glutaredoxin 1 protects dopaminergic cells by increased protein glutathionylation in experimental Parkinson's disease. Antioxid Redox Signal. 17(12):1676-1693. https://doi.org/10.1089/ars.2011.4474

Rodriguez-Rocha H, Garcia Garcia A, Pickett C, Li S, Jones J, Chen H, Webb B, Choi J, Zhou Y, Zimmerman MC et al. 2013. Compartmentalized oxidative stress in dopaminergic cell death induced by pesticides and complex I inhibitors: Distinct roles of superoxide anion and superoxide dismutases. Free Radic Biol Med. 61:370-383. https://doi.org/10.1016/j.freeradbiomed.2013.04.021

Roedding AS, Tong SY, Au-Yeung W, Li PP, Warsh JJ. 2013. Chronic oxidative stress modulates TRPC3 and TRPM2 channel expression and function in rat primary cortical neurons: Relevance to the pathophysiology of bipolar disorder. Brain Res. 1517:16-27. https://doi.org/10.1016/j.brainres.2013.04.025

Roede JR, Hansen JM, Go YM, Jones DP. 2011. Maneb and paraquat-mediated neurotoxicity: Involvement of peroxiredoxin/thioredoxin system. Toxicol Sci. 121(2):368-375. https://doi.org/10.1093/toxsci/kfr058

Roede JR, Uppal K, Park Y, Tran V, Jones DP. 2014. Transcriptome–metabolome wide association study (TMWAS) of maneb and paraquat neurotoxicity reveals network level interactions in toxicologic mechanism. Toxicol Rep. 1:435-444.

Rohrdanz E, Schmuck G, Ohler S, Kahl R. 2001. The influence of oxidative stress on catalase and MnSOD gene transcription in astrocytes. Brain Res. 900(1):128-136. https://doi.org/10.1016/s0006-8993(01)02277-6

Rossi L, Marchese E, Lombardo MF, Rotilio G, Ciriolo MR. 2001. Increased susceptibility of copper-deficient neuroblastoma cells to oxidative stress-mediated apoptosis. Free Radic Biol Med. 30(10):1177-1187.

Ruggeri P, Farina AR, Di Ianni N, Cappabianca L, Ragone M, Ianni G, Gulino A, Mackay AR. 2014. The TrkAIII oncoprotein inhibits mitochondrial free radical ROS-induced death of SH-SY5Y neuroblastoma cells by augmenting SOD2 expression and activity at the mitochondria, within the context of a tumour stem cell-like phenotype. PLoS One. 9(4):e94568. https://doi.org/10.1371/journal.pone.0094568

Said SI, Pakbaz H, Berisha HI, Raza S. 2000. NMDA receptor activation: Critical role in oxidant tissue injury. Free Radic Biol Med. 28(8):1300-1302.

Sanders LH, Paul KC, Howlett EH, Lawal H, Boppana S, Bronstein JM, Ritz B, Greenamyre JT. 2017. Editor's highlight: Base excision repair variants and pesticide exposure increase Parkinson's disease risk. Toxicol Sci. 158(1):188-198. https://doi.org/10.1093/toxsci/kfx086

Sandstrom J, Broyer A, Zoia D, Schilt C, Greggio C, Fournier M, Do KQ, Monnet-Tschudi F. 2017. Potential mechanisms of development-dependent adverse effects of the herbicide paraquat in 3D rat brain cell cultures. Neurotoxicology. 60:116-124. https://doi.org/10.1016/j.neuro.2017.04.010

Sandstrom von Tobel J, Zoia D, Althaus J, Antinori P, Mermoud J, Pak HS, Scherl A, Monnet-Tschudi F. 2014. Immediate and delayed effects of subchronic paraquat exposure during an early differentiation stage in 3D-rat brain cell cultures. Toxicol Lett. 230(2):188-197. https://doi.org/10.1016/j.toxlet.2014.02.001

Sapolsky RM, Packan DR, Vale WW. 1988. Glucocorticoid toxicity in the hippocampus: In vitro demonstration. Brain Res. 453(1-2):367-371. https://doi.org/10.1016/0006-8993(88)90180-1

Sasaki N, Baba N, Matsuo M. 2001. Cytotoxicity of reactive oxygen species and related agents toward undifferentiated and differentiated rat phenochromocytoma PC12 cells. Biol Pharm Bull. 24(5):515-519.

Sashourpour M, Zahri S, Radjabian T, Ruf V, Pan-Montojo F, Morshedi D. 2017. A study on the modulation of alpha-synuclein fibrillation by Scutellaria pinnatifida extracts and its neuroprotective properties. PLoS One. 12(9):e0184483. https://doi.org/10.1371/journal.pone.0184483

Schmuck G, Ahr HJ, Schluter G. 2000. Rat cortical neuron cultures: An in vitro model for differentiating mechanisms of chemically induced neurotoxicity. In Vitro Mol Toxicol. 13(1):37-50.

Schmuck G, Rohrdanz E, Tran-Thi QH, Kahl R, Schluter G. 2002. Oxidative stress in rat cortical neurons and astrocytes induced by paraquat in vitro. Neurotox Res. 4(1):1-13. https://doi.org/10.1080/10298420290007574

Schmuck G, Schluter G. 1996. An in vitro model for toxicological investigations of environmental neurotoxins in primary neuronal cell cultures. Toxicol Ind Health. 12(5):683-696. https://doi.org/10.1177/074823379601200507

Shen W, Wang L, Pi R, Li Z, Rikang W. 2015. L-F001, a multifunctional ROCK inhibitor prevents paraquat-induced cell death through attenuating ER stress and mitochondrial dysfunction in PC12 cells. Biochem Biophys Res Commun. 464(3):794-799. https://doi.org/10.1016/j.bbrc.2015.07.035

Shimizu K, Matsubara K, Ohtaki K, Shiono H. 2003. Paraquat leads to dopaminergic neural vulnerability in organotypic midbrain culture. Neurosci Res. 46(4):523-532.

Singh M, Murthy V, Ramassamy C. 2012. Standardized extracts of Bacopa monniera protect against MPP+- and paraquat-induced toxicity by modulating mitochondrial activities, proteasomal functions, and redox pathways. Toxicol Sci. 125(1):219-232. https://doi.org/10.1093/toxsci/kfr255

Singh SP, Chhunchha B, Fatma N, Kubo E, Singh SP, Singh DP. 2016. Delivery of a protein transduction domain-mediated Prdx6 protein ameliorates oxidative stress-induced injury in human and mouse neuronal cells. Am J Physiol Cell Physiol. 310(1):C1-16. https://doi.org/10.1152/ajpcell.00229.2015

Snider BJ, Moss JL, Revilla FJ, Lee CS, Wheeler VC, Macdonald ME, Choi DW. 2003. Neocortical neurons cultured from mice with expanded CAG repeats in the huntingtin gene: Unaltered vulnerability to excitotoxins and other insults. Neuroscience. 120(3):617-625. https://doi.org/10.1016/s0306-4522(03)00382-8

Song C, Kanthasamy A, Jin H, Anantharam V, Kanthasamy AG. 2011. Paraquat induces epigenetic changes by promoting histone acetylation in cell culture models of dopaminergic degeneration. Neurotoxicology. 32(5):586-595. https://doi.org/10.1016/j.neuro.2011.05.018

Stelmashook EV, Genrikhs EE, Aleksandrova OP, Amelkina GA, Zelenova EA, Isaev NK. 2016. NMDA-receptors are involved in Cu2+/paraquat-induced death of cultured cerebellar granule neurons. Biochemistry (Mosc). 81(8):899-905. https://doi.org/10.1134/s0006297916080113

Stelmashook EV, Isaev NK, Zorov DB. 2007. Paraquat potentiates glutamate toxicity in immature cultures of cerebellar granule neurons. Toxicol Lett. 174(1-3):82-88. https://doi.org/10.1016/j.toxlet.2007.08.012

Sun AY, Li X. 2000. Paraquat is a model environmental neurotoxin for studying Parkinson’s disease. In: Neurotoxic Factors in Parkinson’s Disease and Related Disorders. Springer. p. 247-257.

Sun HN, Kim SU, Huang SM, Kim JM, Park YH, Kim SH, Yang HY, Chung KJ, Lee TH, Choi HS et al. 2010. Microglial peroxiredoxin V acts as an inducible anti-inflammatory antioxidant through cooperation with redox signaling cascades. J Neurochem. 114(1):39-50. https://doi.org/10.1111/j.1471-4159.2010.06691.x

Sun Y, Zheng J, Xu Y, Zhang X. 2018. Paraquat-induced inflammatory response of microglia through HSP60/TLR4 signaling. Hum Exp Toxicol. 37(11):1161-1168. https://doi.org/10.1177/0960327118758152

Tauskela JS, Aylsworth A, Hewitt M, Brunette E, Mealing GA. 2012. Preconditioning induces tolerance by suppressing glutamate release in neuron culture ischemia models. J Neurochem. 122(2):470-481. https://doi.org/10.1111/j.1471-4159.2012.07791.x

Thakar JH, Hassan MN. 1988. Effects of 1-methyl-4-phenyl-1,2,3,6-tetrahydropyridine (MPTP), cyperquat (MPP+) and paraquat on isolated mitochondria from rat striatum, cortex and liver. Life Sci. 43(2):143-149. https://doi.org/10.1016/0024-3205(88)90291-3

Toyoda Y, Erkut C, Pan-Montojo F, Boland S, Stewart MP, Müller DJ, Wurst W, Hyman AA, Kurzchalia TV. 2014. Products of the Parkinson's disease-related glyoxalase DJ-1, D-lactate and glycolate, support mitochondrial membrane potential and neuronal survival. Biol Open. 3(8):777-784. https://doi.org/10.1242/bio.20149399

Unnithan AS, Jiang Y, Rumble JL, Pulugulla SH, Posimo JM, Gleixner AM, Leak RK. 2014. N-acetyl cysteine prevents synergistic, severe toxicity from two hits of oxidative stress. Neurosci Lett. 560:71-76. https://doi.org/10.1016/j.neulet.2013.12.023

Uversky VN, Li J, Bower K, Fink AL. 2002. Synergistic effects of pesticides and metals on the fibrillation of α-synuclein: Implications for Parkinson’s disease. Neurotoxicology. 23(4-5):527-536.

Uversky VN, Li J, Fink AL. 2001. Pesticides directly accelerate the rate of alpha-synuclein fibril formation: A possible factor in Parkinson's disease. FEBS Lett. 500(3):105-108. https://doi.org/10.1016/s0014-5793(01)02597-2

Vaccari A, Saba P. 1995. The tyramine-labelled vesicular transporter for dopamine: A putative target of pesticides and neurotoxins. Eur J Pharmacol. 292(3-4):309-314.

van der Merwe C, van Dyk HC, Engelbrecht L, van der Westhuizen FH, Kinnear C, Loos B, Bardien S. 2017. Curcumin rescues a PINK1 knock down SH-SY5Y cellular model of Parkinson's disease from mitochondrial dysfunction and cell death. Mol Neurobiol. 54(4):2752-2762. https://doi.org/10.1007/s12035-016-9843-0

Velez-Pardo C, Jimenez-Del-Rio M, Lores-Arnaiz S, Bustamante J. 2010. Protective effects of the synthetic cannabinoids CP55,940 and JWH-015 on rat brain mitochondria upon paraquat exposure. Neurochem Res. 35(9):1323-1332. https://doi.org/10.1007/s11064-010-0188-1

Vilas-Boas V, Silva R, Guedes-de-Pinho P, Carvalho F, Bastos ML, Remiao F. 2014. RBE4 cells are highly resistant to paraquat-induced cytotoxicity: Studies on uptake and efflux mechanisms. J Appl Toxicol. 34(9):1023-1030. https://doi.org/10.1002/jat.2926

Vivarelli S, Lenzken SC, Ruepp MD, Ranzini F, Maffioletti A, Alvarez R, Muhlemann O, Barabino SM. 2013. Paraquat modulates alternative pre-mRNA splicing by modifying the intracellular distribution of SRPK2. PLoS One. 8(4):e61980. https://doi.org/10.1371/journal.pone.0061980

Vogt M, Bauer MK, Ferrari D, Schulze-Osthoff K. 1998. Oxidative stress and hypoxia/reoxygenation trigger CD95 (APO-1/Fas) ligand expression in microglial cells. FEBS Lett. 429(1):67-72. https://doi.org/10.1016/s0014-5793(98)00562-6

Vornov JJ, Park J, Thomas AG. 1998. Regional vulnerability to endogenous and exogenous oxidative stress in organotypic hippocampal culture. Exp Neurol. 149(1):109-122. https://doi.org/10.1006/exnr.1997.6673

Wang C, Ko HS, Thomas B, Tsang F, Chew KC, Tay SP, Ho MW, Lim TM, Soong TW, Pletnikova O et al. 2005. Stress-induced alterations in parkin solubility promote parkin aggregation and compromise parkin's protective function. Hum Mol Genet. 14(24):3885-3897. https://doi.org/10.1093/hmg/ddi413

Wang F, Franco R, Skotak M, Hu G, Chandra N. 2014. Mechanical stretch exacerbates the cell death in SH-SY5Y cells exposed to paraquat: Mitochondrial dysfunction and oxidative stress. Neurotoxicology. 41:54-63. https://doi.org/10.1016/j.neuro.2014.01.002

Wang Q, Zhan Y, Ren N, Wang Z, Zhang Q, Wu S, Li H. 2018. Paraquat and MPTP alter microRNA expression profiles, and downregulated expression of miR-17-5p contributes to PQ-induced dopaminergic neurodegeneration. J Appl Toxicol. 38(5):665-677. https://doi.org/10.1002/jat.3571

Wang QL, Guo C, Qi J, Ma JH, Liu FY, Lin SQ, Zhang CY, Xie WD, Zhuang JJ, Li X. 2019. Protective effects of 3beta-angeloyloxy-8beta, 10beta-dihydroxyeremophila-7(11)-en-12, 8alpha-lactone on paraquat-induced oxidative injury in SH-SY5Y cells. J Asian Nat Prod Res. 21(4):364-376. https://doi.org/10.1080/10286020.2017.1423057

Wang X, Zaidi A, Pal R, Garrett AS, Braceras R, Chen XW, Michaelis ML, Michaelis EK. 2009. Genomic and biochemical approaches in the discovery of mechanisms for selective neuronal vulnerability to oxidative stress. BMC Neurosci. 10:12. https://doi.org/10.1186/1471-2202-10-12

Wang XF, Li S, Chou AP, Bronstein JM. 2006. Inhibitory effects of pesticides on proteasome activity: Implication in Parkinson's disease. Neurobiol Dis. 23(1):198-205. https://doi.org/10.1016/j.nbd.2006.02.012

Wu XF, Block ML, Zhang W, Qin L, Wilson B, Zhang WQ, Veronesi B, Hong JS. 2005. The role of microglia in paraquat-induced dopaminergic neurotoxicity. Antioxid Redox Signal. 7(5-6):654-661. https://doi.org/10.1089/ars.2005.7.654

Yan M, Dou T, Lv W, Wang X, Zhao L, Chang X, Zhou Z. 2017. Integrated analysis of paraquat-induced microRNAs-mRNAs changes in human neural progenitor cells. Toxicol In Vitro. 44:196-205. https://doi.org/10.1016/j.tiv.2017.06.010

Yang W, Sun AY. 1998. Paraquat-induced free radical reaction in mouse brain microsomes. Neurochem Res. 23(1):47-53.

Yang W, Tiffany-Castiglioni E. 2005. The bipyridyl herbicide paraquat produces oxidative stress-mediated toxicity in human neuroblastoma SH-SY5Y cells: Relevance to the dopaminergic pathogenesis. J Toxicol Environ Health A. 68(22):1939-1961. https://doi.org/10.1080/15287390500226987

Yang W, Tiffany-Castiglioni E. 2007. The bipyridyl herbicide paraquat induces proteasome dysfunction in human neuroblastoma SH-SY5Y cells. J Toxicol Environ Health A. 70(21):1849-1857. https://doi.org/10.1080/15287390701459262

Yang W, Tiffany-Castiglioni E. 2008. Paraquat-induced apoptosis in human neuroblastoma SH-SY5Y cells: Involvement of p53 and mitochondria. J Toxicol Environ Health A. 71(4):289-299. https://doi.org/10.1080/15287390701738467

Yang W, Tiffany-Castiglioni E, Koh HC, Son IH. 2009. Paraquat activates the IRE1/ASK1/JNK cascade associated with apoptosis in human neuroblastoma SH-SY5Y cells. Toxicol Lett. 191(2-3):203-210. https://doi.org/10.1016/j.toxlet.2009.08.024

Yang W, Tiffany-Castiglioni E, Lee MY, Son IH. 2010. Paraquat induces cyclooxygenase-2 (COX-2) implicated toxicity in human neuroblastoma SH-SY5Y cells. Toxicol Lett. 199(3):239-246. https://doi.org/10.1016/j.toxlet.2010.09.005

Yang WL, Sun AY. 1998. Paraquat-induced cell death in PC12 cells. Neurochem Res. 23(11):1387-1394.

Yoshimura Y, Watanabe Y, Shibuya T. 1993. Inhibitory effects of calcium channel antagonists on motor dysfunction induced by intracerebroventricular administration of paraquat. Pharmacol Toxicol. 72(4-5):229-235.

Zaidi A, Fernandes D, Bean JL, Michaelis ML. 2009. Effects of paraquat-induced oxidative stress on the neuronal plasma membrane Ca(2+)-ATPase. Free Radic Biol Med. 47(10):1507-1514. https://doi.org/10.1016/j.freeradbiomed.2009.08.018

Zhan X, Li F, Chu Q, Pang H. 2018. Effects of PQ's cytotoxicity on secretory vesicles in astroglia: Expression alternation of secretogranin II and its potential interaction with intracellular factors. Biochem Biophys Res Commun. 497(2):675-682. https://doi.org/10.1016/j.bbrc.2018.02.130

Zhang ZX, Song XF, Du XY, Cui Y, Dai JS. 2012. Protective effect of tyrosol on apoptosis in PC12 cell induced by paraquat. Afr J Pharm Pharmacol. 6(29):2224-2228. https://doi.org/10.5897/ajpp12.396

Zhao F, Wang W, Wang C, Siedlak SL, Fujioka H, Tang B, Zhu X. 2017. Mfn2 protects dopaminergic neurons exposed to paraquat both in vitro and in vivo: Implications for idiopathic Parkinson's disease. Biochim Biophys Acta Mol Basis Dis. 1863(6):1359-1370. https://doi.org/10.1016/j.bbadis.2017.02.016

Zhao X, Wang R, Xiong J, Yan D, Li A, Wang S, Xu J, Zhou J. 2017. JWA antagonizes paraquat-induced neurotoxicity via activation of Nrf2. Toxicol Lett. 277:32-40. https://doi.org/10.1016/j.toxlet.2017.04.011

Zhong C, Liu XH, Hao XD, Chang J, Sun X. 2013. Synthesis and biological evaluation of novel neuroprotective agents for paraquat-induced apoptosis in human neuronal SH-SY5Y cells. Eur J Med Chem. 62:187-198. https://doi.org/10.1016/j.ejmech.2012.12.037

Zhou Q, Zhang H, Wu Q, Shi J, Zhou S. 2017. Pharmacological manipulations of autophagy modulate paraquat-induced cytotoxicity in PC12 cells. Int J Biochem Mol Biol. 8(2):13-22.

Zhou Y, Jiang H, Gu J, Tang Y, Shen N, Jin Y. 2013. MicroRNA-195 targets ADP-ribosylation factor-like protein 2 to induce apoptosis in human embryonic stem cell-derived neural progenitor cells. Cell Death Dis. 4:e695. https://doi.org/10.1038/cddis.2013.195

Zhou Y, Li F, Tian X, Wang B, Ding M, Pang H. 2014. Changes in phosphatidylinositol 3-kinase 55 kDa gamma expression and subcellular localization may be caspase 6 dependent in paraquat-induced SH-SY5Y apoptosis. Hum Exp Toxicol. 33(7):761-771. https://doi.org/10.1177/0960327113499044