# Appendix C Data Extraction Elements for Human Studies

Table C-1 Data Extraction Elements for Human Studies

Element Type | Element
Funding | Funding source(s)
Funding | Reporting of conflict of interest by authors and/or translators (*reporting bias)
Subjects | Study population name/description
| Dates of study and sampling timeframe
| Geography (country, region, state, etc.)
| Demographics (sex, race/ethnicity, age or life stage and exposure and outcome assessment)
| Number of subjects (target, enrolled, n per group in analysis, and participation/follow-up rates) (*missing data bias)
| Inclusion/exclusion criteria/recruitment strategy (*selection bias)
| Description of reference group (*selection bias)
Methods | Study design (e.g., prospective or retrospective cohort, nested case-control study, cross-sectional, population-based case-control study, intervention, case report)
| Length of follow-up (*information bias)
| Health outcome category, e.g., neurodevelopment
| Health outcome, e.g., memory (*reporting bias)
| Diagnostic or methods used to measure health outcome (*information bias)
| Confounders or modifying factors and how considered in analysis (e.g., included in final model, considered for inclusion but determined not needed (*confounding bias)
| Substance name and CASRN
| Exposure assessment (e.g., blood, urine, hair, air, drinking water, job classification, residence, administered treatment in controlled study) (*information bias)
| Methodological details for exposure assessment (e.g., high-performance liquid chromatography-mass spectrometry/mass spectrometry, limit of detection) (*information bias)
| Statistical methods (*information bias)
Results | Exposure levels (e.g., mean, median, measures of variance as presented in paper, such as standard deviation, standard error of the mean, 75th/90th/95th percentile, minimum/maximum); range of exposure levels, number of exposed cases
| Statistical findings (e.g., adjusted β, standardized mean difference, adjusted odds ratio, standardized mortality ratio, relative risk) or description of qualitative results. When possible, OHAT will convert measures of effect to a common metric with associated 95% confidence intervals. Most often, measures of effect for continuous data are expressed as mean difference, standardized mean difference, and percent control response. Categorical data are typically expressed as odds ratio, relative risk (also called risk ratio), or β values, depending on what metric is most commonly reported in the included studies and on OHAT’s ability to obtain information for effect conversions from the study or through author query.
| If not presented in the study, statistical power can be assessed during data extraction using an approach that can detect a 10% to 20% change from response by control or referent group for continuous data, or a risk ratio or odds ratio of 1.5 to 2 for categorical data, using the prevalence of exposure or prevalence of outcome in the control or referent group to determine sample size. For categorical data where the sample sizes of exposed and control or referent groups differ, the sample size of the exposed group will be used to determine the relative power category. Recommended sample sizes to achieve 80% power for a given effect size (i.e., 10% or 20% change from control) will be compared with sample sizes used in the study to categorize statistical power as “appears to be adequately powered” (sample size for 80% power met), “somewhat underpowered” (sample size is 75% to <100% of number required for 80% power), “underpowered” (sample size is 50% to <75% of number required for 80% power), or “severely underpowered” (sample size is <50% of number required for 80% power).
| Observations on dose response (e.g., trend analysis, description of whether dose-response shape appears to be monotonic, non-monotonic)
Other | Documentation of author queries, use of digital rulers to estimate data values from figures, exposure unit, and statistical result conversions, etc.