# Appendix B Detailed Inclusion/Exclusion Criteria

Table B-1 Detailed Inclusion and Exclusion Criteria to Determine Study Eligibility^a^

Evidence Stream | Inclusion Criteria | Exclusion Criteria (or Blank if None)
Participants/Population (Human Studies or Experimental Model Systems)
Human | No restrictions on sex, age, life stage (including in utero exposure) at time of exposure or outcome assessment No restrictions on country of residence/origin, lifestyle, race/ethnicity, or occupation
Animal | No restrictions on sex, age, species (including Drosophila and C. elegans), or life stage at exposure or outcome assessment | Studies in non-animal organisms (e.g., plants, fungi, protists, bacteria)
In Vitro | Studies involving an in vitro exposure system and neurological measures directed at cellular, biochemical, and molecular mechanisms that might explain how exposure to paraquat leads to Parkinson’s disease
Exposure
Human | Exposure to paraquat dichloride (CASRN 1910-42-5) based on administered dose or concentration, biomonitoring data (e.g., urine, blood, or other specimens), environmental measures (e.g., air, water levels), or indirect measures (e.g., job title)
Animal | Exposure to paraquat dichloride based on administered dose or concentration or biomonitoring data (e.g., urine, blood, or other specimens) No restrictions on route of administration
In Vitro | Exposure to paraquat dichloride based on administered dose or concentration
Comparators
Human | Humans exposed to lower levels (or no exposure/exposure below detection levels) of paraquat dichloride
Animal | Study must include vehicle or untreated control group
In Vitro | Study must include vehicle or untreated control group
Outcomes
Human | [underlined: Primary outcomes] (following in vivo exposure to paraquat dichloride): Diagnosis of Parkinson’s disease and/or clinical observations, neurobehavioral, or neuropathological outcomes typically associated with Parkinson’s disease following in vivo exposure; focusing on tissue level and functional abnormalities, descriptive and/or functional assessment of the central nervous system, including the nigrostriatal (dopamine) system; examples of relevant neurobehavioral outcomes include tremor, bradykinesia, rigidity, and postural instability [underlined: Secondary outcomes] (following in vivo exposure to paraquat dichloride): Targeted molecular assays that investigate proposed cellular, biochemical, and/or molecular pathways for the etiology of Parkinson’s disease following in vivo exposure | Studies reporting on toxicity in organs or tissues not associated with the central or peripheral nervous system
Animal | [underlined: Primary outcomes] (following in vivo exposure to paraquat dichloride): Neurobehavioral or neuropathological outcomes, focusing on whole body and tissue level abnormalities typically associated with Parkinson’s disease following in vivo exposure; endpoints might include motor activity and coordination, sensorimotor reflexes, effects on cognitive function, quantitative or qualitative assessment of dopaminergic neuron counts in the substantia nigra and dopaminergic neuron terminals in the striatum, and other descriptive and/or functional assessments of the central nervous system, including the nigrostriatal (dopamine) system, which are considered hallmarks of Parkinson’s disease (e.g., detection of intracytoplasmic Lewy bodies) [underlined: Secondary outcomes] (following in vivo exposure to paraquat dichloride): Targeted molecular assays that investigate proposed cellular, biochemical, and/or molecular pathways for the etiology of Parkinson’s disease following in vivo exposure, including measures of oxidative stress, inflammation, mitochondrial and/or proteasomal dysfunction, dopamine and metabolite levels in the nigrostriatal pathway, or other key molecular initiating events related to parkinsonism | Studies reporting on toxicity in organs or tissues not associated with the central or peripheral nervous system
In Vitro | Following [underlined: in vitro exposure] to paraquat dichloride: In vitro assays investigating either cellular responses commonly attributed to Parkinson’s disease (e.g., assessment of functionality, integrity, and viability for nerve cells critical to the nigrostriatal [dopamine] system) or generic cellular responses commonly attributed to paraquat exposure but are not unique to Parkinson’s disease (e.g., measures of oxidative stress and mitochondria dysfunction in nerve cells, epigenetic changes) Mechanistic assays investigating proposed pathways for the etiology of Parkinson’s disease (e.g., enzyme interactions, cell signaling) | Studies reporting on toxicity unrelated to the central or peripheral nervous system
Publications (e.g., Language Restrictions, Use of Conference Abstracts)
Human, Animal, In Vitro | Study must contain original data Studies published in a language other than English will be collected and categorized by health effect or mechanism to the extent they can be categorized without full translation as extensive translation and level of effort are beyond the goals of this scoping review | Articles with no original data (e.g., editorial or review^b^) Studies published in abstract form only (grant awards, conference abstracts) Retracted articles Non-English language articles that cannot be categorized based on English abstract

^a^ These criteria were developed from the PECO statement outlined in Table 1.

^b^ Relevant reviews are used as background and for reference scanning.