# Appendix A Literature Search Strategy

Table A-1 Literature Search Strategy

Database | Search Parameters
Embase Date of original search: April 6, 2017; 107 results Date of search update: May 24, 2018; 242 results | Limits; original search: None Limits; search update: 2017 to present OR added since April 1, 2017; Embase or Embase Classic; no automatic term mapping Search Terms: (paraquat OR 1910-42-5 OR gramoxone OR methyl-viologen OR paragreen-A) AND (alpha-synuclein OR apoptosis OR astrocyte OR astrocytes OR ataxia OR autophagy OR axon OR axonal OR axons OR bradykinesia OR brain OR central-nervous OR dendrite OR dendrites OR dentritic OR dj-1 OR dopamine OR dopaminergic OR gait OR ganglia OR glial OR gliosis OR glutamate OR glutamates OR Glutamic Acids OR glutathione OR Lewy bodies OR lewy body OR locomotion OR locomotor-activity OR lrrk2 OR Mesencephalon OR Mesencephalons OR microglia OR microglial OR microglials OR midbrain OR mitochondria OR Mitochondrial OR Mitochondrion OR motor-activity OR mpp OR mptp OR NADPH-oxidase OR nerve OR nerves OR nervous OR neural OR neurobehavior OR neurobehavioral OR neurobehaviour OR neurobehavioural OR neuroblastoma OR neurodegeneration OR neurodegenerative OR neuroglia OR neurological OR neuromotor OR neuron OR neuronal OR neuronopathy OR neurons OR neuropathies OR neuropathology OR neuropathy OR neurotoxic OR neurotoxicity OR neurotransmitter OR neurotransmitters OR nigral OR nigrostriatal OR nitric-oxide OR nitrosative-stress OR oxidative-stress OR paralysis-agitans OR parkin OR parkinson OR parkinsons OR parkinsonian OR parkinsonism OR pink1 OR reactive-oxygen-species OR rigidity OR snpc OR striatal OR striatum OR substantia-nigra OR synapse OR synapses OR synaptic OR synuclein OR synucleins OR tau OR tauopathies OR tauopathology OR tauopathy OR Thioredoxin-Disulfide OR thioredoxin-reductase OR tremor OR tremors OR Tyrosine 3-Monooxygenase OR tyrosine-hydroxylase OR ubiquitin)
PubMed Date of original search: April 6, 2017; 3,501 results Date of search update: May 24, 2018; 307 results | Limits; original search: None Limits; search update: (2017/4/1:3000[mhda] OR 2017/4/1:3000 [crdt] OR 2017/4/1:3000 [edat] OR 2017/4/1[PDAT]:3000[PDAT]) Search Terms: (paraquat[tiab] OR paraquat[mh] OR gramoxone[tiab] OR methyl-viologen[tiab] OR paragreen-A[tiab]) AND (alpha-synuclein[tiab] OR alpha-synuclein[mh] OR apoptosis[tiab] OR apoptosis[mh] OR astrocyte[tiab] OR astrocytes[tiab] OR astrocytes[mh] OR ataxia[tiab] OR autophagy[tiab] OR autophagy[mh] OR axon[tiab] OR axonal[tiab] OR axons[tiab] OR axons[mh] OR bradykinesia[tiab] OR brain[tiab] OR central-nervous[tiab] OR dendrite[tiab] OR dendrites[tiab] OR dentritic[tiab] OR dj-1[tiab] OR dopamine[mh] OR dopamine[tiab] OR Dopamine Plasma Membrane Transport Proteins[mh] OR dopaminergic[tiab] OR gait[tiab] OR gait[mh] OR ganglia[tiab] OR glial[tiab] OR gliosis[tiab] OR gliosis[mh] OR glutamate[tiab] OR glutamates[mh] OR glutamates[tiab] OR Glutamic Acids[tiab] OR glutathione[tiab] OR glutathione[mh] OR Lewy bodies[tiab] OR lewy body[tiab] OR locomotion[mh] OR locomotion[tiab] OR locomotor-activity[tiab] OR lrrk2[tiab] OR Mesencephalon[tiab] OR Mesencephalons[tiab] OR microglia[tiab] OR microglial[tiab] OR microglials[tiab] OR midbrain[tiab] OR mitochondria[tiab] OR mitochondria[mh] OR Mitochondrial[tiab] OR Mitochondrion[tiab] OR motor-activity[tiab] OR motor-activity[mh] OR mpp[tiab] OR mptp[tiab] OR NADPH-oxidase[mh] OR NADPH-oxidase[tiab] OR nerve[tiab] OR nerves[tiab] OR nervous[tiab] OR nervous-system[mh] OR nervous-system-diseases[mh] OR nervous-system-physiological-processes[mh] OR neural[tiab] OR neurobehavior[tiab] OR neurobehavioral[tiab] OR neurobehaviour[tiab] OR neurobehavioural[tiab] OR neuroblastoma[tiab] OR neuroblastoma[mh] OR neurodegeneration[tiab] OR neurodegenerative[tiab] OR neuroglia[tiab] OR neurological[tiab] OR neuromotor[tiab] OR neuron[tiab] OR neuronal[tiab] OR neuronopathy[tiab] OR neurons[tiab] OR neuropathies[tiab] OR neuropathology[tiab] OR neuropathy[tiab] OR neurotoxic[tiab] OR neurotoxicity[tiab] OR neurotransmitter[tiab] OR neurotransmitter agents[mh] OR neurotransmitter agents[Pharmacological Action] OR neurotransmitters[tiab] OR nigral[tiab] OR nigrostriatal[tiab] OR nitric-oxide[tiab] OR nitric-oxide[mh] OR nitric-oxide-synthase[mh] OR nitrosative-stress[tiab] OR oxidative-stress[tiab] OR paralysis-agitans[tiab] OR parkin[tiab] OR parkin protein[supplementary concept] OR parkinson[tiab] OR parkinsons[tiab] OR parkinson's[tiab] OR parkinsonian[tiab] OR parkinsonism[tiab] OR pink1[tiab] OR reactive-oxygen-species[tiab] OR reactive-oxygen-species[mh] OR rigidity[tiab] OR snpc[tiab] OR striatal[tiab] OR striatum[tiab] OR substantia-nigra[tiab] OR synapse[tiab] OR synapses[tiab] OR synaptic[tiab] OR synuclein[tiab] OR synucleins[tiab] OR synucleins[mh] OR tau[tiab] OR tau proteins[mh] OR tauopathies[tiab] OR tauopathology[tiab] OR tauopathy[tiab] OR Thioredoxin-Disulfide[tiab] OR Thioredoxin-Disulfide Reductase[mh] OR thioredoxin-reductase[tiab] OR tremor[tiab] OR tremors[tiab] OR Tyrosine 3-Monooxygenase[mh] OR Tyrosine 3-Monooxygenase[tiab] OR tyrosine-hydroxylase[tiab] OR ubiquitin[tiab] OR ubiquitin[mh])
Web of Science Date of original search: April 6, 2017; 3,551 results Date of search update: May 24, 2018; 252 results | Original search and search update parameters: All terms searched in Title, Abstract, or Keywords; Indexes=SCI-EXPANDED, SSCI, CPCI-S, CPCI-SSH, BKCI-S, BKCI-SSH, CCR-EXPANDED, IC; Timespan=All years Search Terms: (paraquat OR 1,1'-Dimethyl-4,4'-bipyridinium-dichloride OR 1910-42-5 OR gramoxone OR methyl-viologen OR paragreen-A) AND (alpha-synuclein OR apoptosis OR astrocyte OR astrocytes OR ataxia OR autophagy OR axon OR axonal OR axons OR bradykinesia OR brain OR central-nervous OR dendrite OR dendrites OR dentritic OR dj-1 OR dopamine OR dopaminergic OR gait OR ganglia OR glial OR gliosis OR glutamate OR glutamates OR Glutamic Acids OR glutathione OR Lewy bodies OR lewy body OR locomotion OR locomotor-activity OR lrrk2 OR Mesencephalon OR Mesencephalons OR microglia OR microglial OR microglials OR midbrain OR mitochondria OR Mitochondrial OR Mitochondrion OR motor-activity OR mpp OR mptp OR NADPH-oxidase OR nerve OR nerves OR nervous OR neural OR neurobehavior OR neurobehavioral OR neurobehaviour OR neurobehavioural OR neuroblastoma OR neurodegeneration OR neurodegenerative OR neuroglia OR neurological OR neuromotor OR neuron OR neuronal OR neuronopathy OR neurons OR neuropathies OR neuropathology OR neuropathy OR neurotoxic OR neurotoxicity OR neurotransmitter OR neurotransmitters OR nigral OR nigrostriatal OR nitric-oxide OR nitrosative-stress OR oxidative-stress OR paralysis-agitans OR parkin OR parkinson OR parkinsons OR parkinson's OR parkinsonian OR parkinsonism OR pink1 OR reactive-oxygen-species OR rigidity OR snpc OR striatal OR striatum OR substantia-nigra OR synapse OR synapses OR synaptic OR synuclein OR synucleins OR tau OR tauopathies OR tauopathology OR tauopathy OR Thioredoxin-Disulfide OR thioredoxin-reductase OR tremor OR tremors OR Tyrosine 3-Monooxygenase OR tyrosine-hydroxylase OR ubiquitin)
SCOPUS Date of original search: April 6, 2017; 128 results Date of search update: May 24, 2018; 0 results | Original search and search update parameters: All terms searched in Title, Abstract, or Keywords; Indexes=SCI-EXPANDED, SSCI, CPCI-S, CPCI-SSH, BKCI-S, BKCI-SSH, CCR-EXPANDED, IC; Timespan=All years Search Terms; original search: (paraquat OR 1,1'-Dimethyl-4,4'-bipyridinium-dichloride OR 1910-42-5 OR gramoxone OR methyl-viologen OR paragreen-A) Search Terms; search update: (paraquat OR 1,1'-Dimethyl-4,4'-bipyridinium-dichloride OR 1910-42-5 OR gramoxone OR methyl-viologen OR paragreen-A) AND (alpha-synuclein OR apoptosis OR astrocyte OR astrocytes OR ataxia OR autophagy OR axon OR axonal OR axons OR bradykinesia OR brain OR central-nervous OR dendrite OR dendrites OR dentritic OR dj-1 OR dopamine OR dopaminergic OR gait OR ganglia OR glial OR gliosis OR glutamate OR glutamates OR Glutamic Acids OR glutathione OR Lewy bodies OR lewy body OR locomotion OR locomotor-activity OR lrrk2 OR Mesencephalon OR Mesencephalons OR microglia OR microglial OR microglials OR midbrain OR mitochondria OR Mitochondrial OR Mitochondrion OR motor-activity OR mpp OR mptp OR NADPH-oxidase OR nerve OR nerves OR nervous OR neural OR neurobehavior OR neurobehavioral OR neurobehaviour OR neurobehavioural OR neuroblastoma OR neurodegeneration OR neurodegenerative OR neuroglia OR neurological OR neuromotor OR neuron OR neuronal OR neuronopathy OR neurons OR neuropathies OR neuropathology OR neuropathy OR neurotoxic OR neurotoxicity OR neurotransmitter OR neurotransmitters OR nigral OR nigrostriatal OR nitric-oxide OR nitrosative-stress OR oxidative-stress OR paralysis-agitans OR parkin OR parkinson OR parkinsons OR parkinson's OR parkinsonian OR parkinsonism OR pink1 OR reactive-oxygen-species OR rigidity OR snpc OR striatal OR striatum OR substantia-nigra OR synapse OR synapses OR synaptic OR synuclein OR synucleins OR tau OR tauopathies OR tauopathology OR tauopathy OR Thioredoxin-Disulfide OR thioredoxin-reductase OR tremor OR tremors OR Tyrosine 3-Monooxygenase OR tyrosine-hydroxylase OR ubiquitin)
TOXLINE Date of original search: April 6, 2017; 1,089 results Date of search update: May 24, 2018; 0 results | Original search and search update parameters: All terms searched in Title, Abstract, or Keywords; Limits; original search: Exclude PubMed Records; Search exact words Limits; search update: Exclude PubMed Records; Do NOT add chemical synonyms and CASRNs to search; Search exact words Search Terms: (paraquat OR 1,1'-Dimethyl-4,4'-bipyridinium-dichloride OR 1910-42-5 OR gramoxone OR methyl-viologen OR paragreen-A) AND (alpha-synuclein OR apoptosis OR astrocyte OR astrocytes OR ataxia OR autophagy OR axon OR axonal OR axons OR bradykinesia OR brain OR central-nervous OR dendrite OR dendrites OR dentritic OR dj-1 OR dopamine OR dopaminergic OR gait OR ganglia OR glial OR gliosis OR glutamate OR glutamates OR Glutamic Acids OR glutathione OR Lewy bodies OR lewy body OR locomotion OR locomotor-activity OR lrrk2 OR Mesencephalon OR Mesencephalons OR microglia OR microglial OR microglials OR midbrain OR mitochondria OR Mitochondrial OR Mitochondrion OR motor-activity OR mpp OR mptp OR NADPH-oxidase OR nerve OR nerves OR nervous OR neural OR neurobehavior OR neurobehavioral OR neurobehaviour OR neurobehavioural OR neuroblastoma OR neurodegeneration OR neurodegenerative OR neuroglia OR neurological OR neuromotor OR neuron OR neuronal OR neuronopathy OR neurons OR neuropathies OR neuropathology OR neuropathy OR neurotoxic OR neurotoxicity OR neurotransmitter OR neurotransmitters OR nigral OR nigrostriatal OR nitric-oxide OR nitrosative-stress OR oxidative-stress OR paralysis-agitans OR parkin OR parkinson OR parkinsons OR parkinson's OR parkinsonian OR parkinsonism OR pink1 OR reactive-oxygen-species OR rigidity OR snpc OR striatal OR striatum OR substantia-nigra OR synapse OR synapses OR synaptic OR synuclein OR synucleins OR tau OR tauopathies OR tauopathology OR tauopathy OR Thioredoxin-Disulfide OR thioredoxin-reductase OR tremor OR tremors OR Tyrosine 3-Monooxygenase OR tyrosine-hydroxylase OR ubiquitin)