# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2473-4756

DOI: https://dx.doi.org/10.22427/NTP-RR-15

Report Series: NTP Research Report Series

Report Series Number: 15

Official citation: Boyd WA, Boyles AL, Blain RB, Skuce CR, Engstrom AK, Walker VR, Thayer KA, Rooney AA. 2020. NTP research report on the scoping review of potential human health effects associated with exposures to neonicotinoid pesticides. Research Triangle Park, NC: National Toxicology Program. Research Report 15.