# Peer Review

The National Toxicology Program (NTP) conducted a peer review of the draft NTP Research Report on the Scoping Review of Potential Human Health Effects Associated with Exposures to Neonicotinoid Pesticides by letter in February 2019 by the experts listed below. Reviewer selection and document review followed established NTP practices. The reviewers were charged to:

1. Peer review the Draft NTP Research Report on the Scoping Review of Potential Human Health Effects Associated with Exposures to Neonicotinoid Pesticides and comment on the adequacy of the scoping report in identifying and summarizing the relevant literature.

## Peer Reviewers

- Susanne Hougaard Bennekou, Ph.D.
  Senior Advisor, National Food Institute
  Technical University of Denmark
  Kongens Lyngby, Denmark
- Marian McDonagh, Ph.D.
  Professor, School of Medicine
  Oregon Health & Science University
  Portland, Oregon, USA