# Results

## Literature Search Results

The screening results and reasons for exclusion are outlined in the study selection diagram (Figure 1). The electronic database searches retrieved 3,068 individual references, and eight additional references were identified by reviewing the reference lists of published reviews. After duplicate removal, a total of 3,056 individual references were screened for study inclusion in the title-and-abstract screen. Of these, 2,706 studies were excluded as not relevant to study eligibility criteria, including more than half that mentioned relevant neonicotinoid exposures but did not contain information relevant to human health effects as defined by the eligibility criteria. These studies included pesticide efficacy studies in pets that do not report on the health of the animals, as well as studies of effects on honeybees or other nontarget organisms that did not contain information directly relevant to human health or were not designed to model human health effects (e.g., ecological hazard studies). More information on effects of the neonicotinoid pesticides clothianidin, imidacloprid, and thiamethoxam on bees is available in technical reports and risk assessments performed by the European Food Safety Authority (https://www.efsa.europa.eu/en/press/news/180228).

Of the 247 studies identified as potentially relevant to human health effects and reviewed in the full-text screen, 53 were excluded due to lack of human health effects information and 191 studies were considered relevant to study eligibility criteria and binned according to evidence stream including 25 studies in humans and 86 in mammals (Figure 1).

### Human Health-relevant Studies

The 191 included studies were classified by broad health effects categories, evidence stream, and the neonicotinoid(s) studied (Figure 2); the studies were further classified by animal species and/or study type (e.g., case reports or epidemiological studies in humans) in the interactive version of the figure here: [underlined: https://doi.org/10.22427/NTP-DATA-002-00069-0001-0000-8] (NTP, 2019). Note that some studies evaluated multiple health effects or evidence streams and may be listed multiple times.

Figure 2

Number of Studies Evaluating Neonicotinoid Exposures and Outcomes in Humans and Animals

Note: Some studies may have characterized health effects of neonicotinoids in multiple evidence streams and therefore may be listed multiple times. Row and column totals and grand total shown in the figure represent counts of distinct references. Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-002-00069-0001-0000-8) (NTP, 2019).

Neurological effects were the most commonly studied health effect (86 studies with one study containing both animal and in vitro data) across all evidence streams with 42 animal studies, three human epidemiological studies, and 18 human case reports (Table 2). The majority of in vitro studies investigated endpoints associated with neurological effects (24 studies), followed by five studies of developmental effects, and 19 in vitro studies classified as “Other” effects that consisted mainly of cytotoxicity and genotoxicity studies. Aside from case reports, the largest pocket of human epidemiological evidence consisted of four studies reporting developmental or congenital outcomes. Several alternative model organism studies were identified including 25 fish studies reporting a range of effects, and three studies of Caenorhabditis elegans reporting developmental, reproductive, neurological, and other effects. Overall, imidacloprid was the most commonly studied neonicotinoid (127 studies), followed by acetamiprid (34 studies), clothianidin (23 studies), thiamethoxam (23 studies), thiacloprid (20 studies), nitenpyram (7 studies), and dinotefuran (4 studies).

Table 2 Epidemiological Studies Evaluating Neonicotinoid Exposures and Effects

Study Design (Location/Subjects) [n] | Exposure Assessment (Life Stage at Exposure) | Outcomes | Results | Study
Case-control (California/Infants or fetuses with congenital heart defects from the California Birth Defects Monitoring Program) [101 cases, 785 controls] | Imidacloprid; neonicotinoid pesticide group Exposure estimated categorically (none/any) from state pesticide use records between 1997–2006 and proximity of residence to use (in utero) | Group of 4 congenital heart defects (Tetralogy of Fallot) | ↑* adjORs for imidacloprid and ↑* neonicotinoid pesticide group exposures ↑* and congenital heart defects | Carmichael et al. (2014)
Case-control (California/Child participants of the Childhood Autism Risks from Genetics and Environment study) [407 cases, 262 controls] | Imidacloprid Exposure estimated categorically (never/ever; and prenatal never/ever/consistent/occasional) based on maternal-reported household usage of flea or tick control on pets (in utero through childhood) | Autism spectrum disorder | ↑* adjOR in consistent users; ↑ exposure window analysis found ↑ nonsignificant increase in adjORs during ↑ pregnancy (results were considered ↑ imprecise) | Keil et al. (2014)
Cross-sectional (Pakistan/adult pesticide industrial workers; number of industries included not reported) [238 males; 184 exposed, 54 unexposed] | Multiple pesticides including imidacloprid Exposure groups estimated based on industrial size and production of pesticides as opposed to specific chemical exposure, but imidacloprid was measured in plasma of 184 industrial workers (adult) | Hematology and clinical chemistry (several endpoints); clinical symptoms; plasma cholinesterase; oxidative stress/ inflammatory markers (4 endpoints) | ↑* liver enzymes, ↑ oxidative stress markers, ↑ inflammatory markers; ↓ plasma cholinesterase levels, ↑ total antioxidants; [struck: Δ] plasma bilirubin, ↑ albumin, ↑ total proteins, ↑ urea, ↑ creatinine; clinical symptoms including headache followed by dizziness, vomiting, shortness of breath, skin rash were commonly reported (in about 2–20% depending on clinical symptom and size of industry) | Khan et al. (2010)
Case-control (Japan/child and adult with neonicotinoid symptoms) [35 cases, 50 controls] | Multiple insecticides including acetamiprid, thiacloprid, imidacloprid, nitenpyram, clothianidin, thiamethoxam measured in spot urine samples (exposure timing unknown) | Nicotinic symptoms (headache, general fatigue, palpitations or chest pain, abdominal pain, muscle pain/weakness/spasm, cough, postural finger tremor, recent memory loss, and fever) | ↑ Nicotinic symptoms in subjects with ↑ increased levels of thiamethoxam and ↑ DMAP, a metabolite of acetamiprid | Marfo et al. (2015)
Case-control (California/Infants or fetuses with gastroschisis from the California Birth Defects Monitoring Program) [156 cases, 785 controls] | Imidacloprid; neonicotinoid pesticide group Exposure estimated categorically (none/any) from state pesticide use records between 1997–2006 and proximity of residence to use (in utero) | Birth defect (gastroschisis) | ↑ adjORs for imidacloprid and ↑ neonicotinoid pesticide group exposures ↑ and gastroschisis | Shaw et al. (2014)
Case-control (California/Child participants of the California Birth Defects Monitoring Program) [590 cases, 785 controls] | Neonicotinoid pesticide group including imidacloprid Exposure estimated categorically (none/any) from state pesticide use records between 1997–2006 and proximity of residence to use (in utero) | Birth defects (anencephaly, spina bifida, cleft lip with or without cleft palate, or cleft palate only) | ↑ adjORs for anencephaly, ↑ cleft lip with or without cleft palate, ↑ cleft palate only no odds ratio calculated for spina bifida | Yang et al. (2014)

* : statistically significant change in effect reported by authors.

adjOR = adjusted odds ratio.

↑: increased effect reported by authors.

↓: decreased effect reported by authors.

[struck: Δ]: no change in effect reported by authors.

### Neurological and Congenital/Developmental Effects

On the basis of the initial categorization of health effects identified in Table 2, additional study characteristics were captured for the health outcomes with the highest number of studies to evaluate the homogeneity of the endpoints reported and determine whether enough similar evidence would be available for future hazard evaluation of any exposure-outcome pair. Therefore, the remainder of this scoping review focuses on neurological effects (the health effect with the highest number of studies across all evidence streams) and congenital/developmental effects (the highest number of human non-case report studies). Case reports were not included in the focused evaluation because they are generally a medical report on a single subject after an acute high exposure to neonicotinoids rather than a chronic, low-level exposure that may be more representative of exposures to the general population; however, the case reports may provide supporting evidence for potential health effects following high exposures and thus were included in the evidence map.

#### Human Studies

The study designs and outcomes for the six epidemiological studies, including five case-control studies and one cross-sectional study, are summarized in Table 2. All studies evaluated exposure to imidacloprid, and a general neonicotinoid exposure category. Three case-control studies used statewide pesticide use records in California and proximity to residence of participant’s mother during pregnancy to estimate exposures to imidacloprid and neonicotinoids as a group in participants of the California Birth Defects Monitoring Program and reported on different types of birth defect outcomes (Carmichael et al. 2014; Shaw et al. 2014; Yang et al. 2014). A fourth case-control study conducted in California investigated the occurrence of autism spectrum disorder in children participants of the Childhood Autism Risks from Genetics and Environment (CHARGE) study whose mothers reported using flea or tick control on pets within the household during pregnancy or the participant’s childhood (Carmichael et al. 2014; Keil et al. 2014; Khan et al. 2010; Shaw et al. 2014; Yang et al. 2014). The remaining case-control study compared levels of neonicotinoids in the urine (including imidacloprid, acetamiprid, thiacloprid, nitenpyram, clothianidin, and thiamethoxam) of subjects in Japan with nicotinic symptoms including muscle pain, weakness, spasm, finger tremor, or memory loss to those subjects without symptoms (Marfo et al. 2015). The only cross-sectional study measured imidacloprid levels and evaluated biochemical parameters and clinical symptoms including dizziness and shortness of breath in pesticide workers in Pakistan compared with controls (Khan et al. 2010).

#### Animal Studies

The available neurological and developmental or congenital health outcomes in animal models are summarized in Figure 3 and Figure 4, respectively. The majority of the studies were conducted in rats or mice, of various ages and strains, exposed via the oral route of exposure or injection. A few studies were reported in other animal models (fish, bats, C. elegans, and Drosophila). One animal study that mentioned neurological effects was not included as it was a case series on three dogs and, consistent with human studies, case reports were not included. Data extraction was limited to brief descriptions of measured endpoints due to the heterogeneity of endpoints and exposure concentrations investigated across the studies.

Figure 3

Number of Studies Evaluating Neonicotinoid Exposures and Neurological Outcomes in Animals

Note: Some studies may have characterized multiple neurological health effects or multiple neonicotinoids and therefore may be listed multiple times. Row and column totals and grand total shown in the figure represent counts of distinct references. Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-002-00069-0001-0000-8) (NTP, 2019).

Figure 4

Number of Studies Evaluating Neonicotinoid Exposures and Developmental Outcomes in Animals

Notes: No studies examined developmental or congenital effects of dinotefuran, therefore it is not shown here. Some studies may have characterized multiple developmental health effects or multiple neonicotinoids and therefore may be listed multiple times. Row and column totals and grand total shown in the figure represent counts of distinct references. Interactive figure and additional study details in Tableau (https://doi.org/10.22427/NTP-DATA-002-00069-0001-0000-8) (NTP, 2019).

##### Neurological Effects

Although 41 experimental animal studies evaluated neurological effects, the data were heterogeneous with few studies using the same chemical while evaluating the same or similar endpoints (Figure 3). Acetylcholinesterase (AChE) levels after imidacloprid exposure were evaluated in the largest number of studies (nine studies in rats and two studies in fish). Learning and memory in rats and mice were also evaluated in five studies that used disparate methods to characterize different facets of learning and memory including the Morris water maze (Kara et al. 2015; Özdemir et al. 2014), T-maze (Bhaskar et al. 2017), Y-maze (Yoneda et al. 2018), and a behavioral flexibility paradigm (acquisition task followed by reversal tasks) (Sano et al. 2016). Eighteen experimental animal studies assessed the effect of neonicotinoids on motor and sensory function, including general locomotor activity, motor strength, coordination, reflexes, and pain response in rodents or zebrafish, flight path in bats, and different motor endpoints in C. elegans and Drosophila. Other neurological endpoints included anxiety, social behavior, and depression. Twenty-two animal studies investigated neurochemical or other histopathological, structural, or gene expression changes in the brain following exposure to different neonicotinoid pesticides, but as noted, there is little overlap in the specific endpoints evaluated (Figure 3).

##### Developmental Effects

A total of 11 animal studies were identified that reported developmental or congenital effects after exposure to a neonicotinoid pesticide (Figure 4). No studies examined the effects of dinotefuran. Six rodent studies characterized the developmental effects from neonicotinoid exposure during different critical developmental windows, including gestation-only (Babelova et al. 2017; Gawade et al. 2013), gestation and lactation (Gawade et al. 2013; Sano et al. 2016; Tanaka 2012b), lactation-only (Bhaskar and Mohanty 2014), or gestation through adolescence (Gawade et al. 2013; Tanaka 2012a); one study tested imidacloprid effects at three time periods from gestation through adolescence (Gawade et al. 2013). The primary endpoints measured in these rodent studies were body weight (five studies), survival (four studies), skeletal malformations (one study), and sex ratio (one study). Neurodevelopmental effects from these studies are included with neurological effects (Figure 3).

Five studies using alternative toxicological model organisms were also identified. Three zebrafish (Danio rerio) studies and one common carp study assessed the effects of embryonic thiamethoxam, thiacloprid, or imidacloprid exposure on hatching success, embryo development, and morphological abnormalities (Liu et al. 2018; Osterauer and Kohler 2008; Scheil and Kohler 2009; Velisek and Stara 2018). A single C. elegans study exposed hermaphrodite adults and their eggs to clothianidin, thiacloprid, or nitenpyram and characterized the larval development of the offspring (Kudelska et al. 2017).

#### In Vitro Studies

In total, 29 in vitro studies were identified as relevant to human neurological or developmental outcomes, because the studies investigated relevant mechanisms or processes (e.g., effects on nicotinic acetylcholine receptors [nAChRs] or embryonic development) or were conducted in relevant tissue models (e.g., neuron cultures). Eleven of these were related to evaluating the effects on nAChRs as this is the known mechanism in target insects (see Table 3). Eighteen in vitro studies were identified that evaluated other types of endpoints relevant to human neurological or developmental outcomes, and the details of these studies are summarized in Table 4. The majority of these 29 studies tested imidacloprid, and several studies also evaluated the effects of acetamiprid, clothianidin, thiacloprid, or thiamethoxam. Most of the studies evaluating endpoints other than nAChR (n = 10) used primary neurons or neuronal cell lines including human neuroblastoma SH-SY5Y and the rat neuroblastic cell line PC12. These studies also commonly characterized the effects of different neonicotinoids on electrophysiological properties (Alloisio et al. 2015; Camlica et al. 2018; Kimura-Kuroda et al. 2012; Meijer et al. 2015; Meijer et al. 2014), cell viability or morphology (Bal et al. 2010; Camlica et al. 2018; Christen et al. 2017; Kimura-Kuroda et al. 2016; Meijer et al. 2015; Senyildiz et al. 2018; Skandrani et al. 2006), or changes in gene or protein expression (Kawahata and Yamakuni 2018; Kimura-Kuroda et al. 2016; Skandrani et al. 2006; Sugiyama et al. 2015). Five studies evaluated the effect of neonicotinoids on developmental endpoints using a human adrenocortical cell line in conjunction with either primary human umbilical vein endothelial cells (Caron-Beaudoin et al. 2016) or a human placental choriocarcinoma cell line (Caron-Beaudoin et al. 2017), mouse or rabbit embryos (Babelova et al. 2017), mouse oocytes (Gu et al. 2013), or primary mouse Sertoli cells (Babelova et al. 2017; Caron-Beaudoin et al. 2016; Caron-Beaudoin et al. 2017; Gu et al. 2013; Kugathas et al. 2016).

Table 3 In Vitro Studies Evaluating Neonicotinoid Effects on Nicotinic Acetylcholine Receptors

Exposure | Concentrations Tested | Cell Types | Endpoints Evaluated | Study
Imidacloprid | 0.01 to 1 mM | Frog oocytes expressing hybrid nAChR with subunits from various species (rat, chicken, or insect) | Evoked currents; effects of mutations on potency | Bao et al. (2016)
Acetamiprid, Clothianidin, Thiamethoxam | 0.00001 to 0.01 M | Frog oocytes expressing rat recombinant nAChR | Effects on ACh-induced currents | Cartereau et al. (2017)
Imidacloprid | 5 to 95 nM | Drosophila S2 cells expressing hybrid nAChR with subunits from various species (rat and Drosophila) | Affinity of agonist and antagonist binding | Lansdell and Millar (2000)
Imidacloprid | Specific concentrations not reported; only IC50 concentration of 155 nM provided | Sf9 insect cells expressing rat recombinant nAChR | Receptor binding IC50 | Latli et al. (1999)
Imidacloprid; Clothianidin | Up to 300 μM | HEK 293 cell line stably expressing human nAChR | Receptor activation; evoked currents; dose-response relationship of receptor antagonism | Li et al. (2011)
Imidacloprid | About 10 to 500 μM | Frog oocytes expressing nAChRs from embryonic rat muscle | Membrane and single-channel currents | Methfessel (1992)
Imidacloprid | 10 μM | Rat adrenal PC12 cell line | nAChR-channel modifications | Nagata et al. (1996)
Imidacloprid | 10 μM; 0.01, 0.1, 10, 30 μM | Rat brain PC12 cell line | nAChR-channel modifications; whole-cell current electrical activity | Nagata et al. (1998)
Imidacloprid | Specific concentrations not reported; only IC50 of 14 μM provided | Human neuroblastoma SH-SY5Y cell line; rodent brain membranes | Structure activity relationships for receptor binding | Tomizawa and Casida (1999)
Imidacloprid; Thiacloprid | Up to 0.1 mM | Mouse fibroblast M10 cell line stably expressing chicken nAChR | Receptor binding affinity | Tomizawa and Casida (2000)
Imidacloprid; Thiacloprid | Up to about 1 mM | Mouse fibroblast M10 cell line | Receptor binding affinity; agonist potency; antinociceptive effects | Tomizawa et al. (2001)

nAChR = nicotinic acetylcholine receptors; HEK = human embryonic kidney; PC12 = pheochromocytoma.

Table 4 In Vitro Studies Evaluating Neonicotinoid Exposures and Neurological and Developmental Effects

Exposure | Concentrations Tested | Cell Types | Endpoints Evaluated | Study
Neurological Endpoints
Imidacloprid | 1, 10, 100 pM; 1,10, 100 μM | Primary rat cortical neurons | Spontaneous electrical activity | Alloisio et al. (2015)
Imidacloprid | 1, 10, 50, 100, 1000 μM | Primary mouse brain stellate cells | Cell membrane activity | Bal et al. (2010)
Acetamiprid | 1, 10, 100, 1000 μM | Frog sciatic nerves | Nerve action potential amplitude and area; nerve histopathology | Camlica et al. (2018)
Acetamiprid, Clothianidin, Imidacloprid, Thiamethoxam | 1, 10, 100 μM | Rat PC12 cell line | Neurite outgrowth; gene expression | Christen et al. (2017)
Acetamiprid, Clothianidin, Thiacloprid, Thiamethoxam | 1 μM to 1 mM (specific concentrations not reported for each compound) | Purified electric eel AChE | Inhibition of AChE activity; AChE binding kinetics | Gyori et al. (2017)
Imidacloprid | 3, 30, 100 μM | Rat adrenal medulla PC12D cell line; primary rat adrenal chromaffin cells | TH and PNMT gene and protein expression; catecholamine secretion; dopamine content; adrenaline biosynthesis | Kawahata and Yamakuni (2018)
Acetamiprid, Imidacloprid | 1, 10, 100 μM | Rat neonatal cerebellar neurons | Ca^2+^ influxes; neural excitation | Kimura-Kuroda et al. (2012)
Acetamiprid, Imidacloprid | 1 μM | Rat neonatal cerebellar neurons | Gene expression; neuron branching | Kimura-Kuroda et al. (2016)
Imidacloprid | 10 μM | Rat adrenal PC12 cell line | Basal Ca^2+^ levels; inhibition of depolarization-evoked Ca^2+^ | Meijer et al. (2014)
Imidacloprid | 0.1, 1, 10, 100 μM (cell viability) 10 μM (depolarization) | Rat adrenal PC12 cell line | Cell viability; inhibition of depolarization-evoked Ca^2+^ | Meijer et al. (2015)
Acetamiprid, Clothianidin, Imidacloprid, Thiacloprid, Thiamethoxam | 0.125, 0.25, 0.5, 1, 2, 4 mM (cytotoxicity, cell viability) 50, 100, 200, 500 μM (DNA damage) | Human neuroblastoma cell line (SH-SY5Y) | Cytotoxicity; DNA damage | Senyildiz et al. (2018)
Imidacloprid | 50 to 800 μg/mL | Human neuronal cell line (SH-SY5Y) | Cell growth; GRP expression, HSP expression; SH-SY5Y toxicity | Skandrani et al. (2006)
Nitenpyram | 0.1, 1, 10, 100 μM | Cortical neurons | GluR2 protein expression; glutamate toxicity | Sugiyama et al. (2015)
Developmental Endpoints
Acetamiprid, Clothianidin, Thiacloprid, Thiamethoxam | 0.1, 1, 10, and 100 μM | Fertilized mouse and rabbit embryos | Embryo development; blastomere number; cell death; blastocyst quality | Babelova et al. (2017)
Imidacloprid, Thiacloprid, Thiamethoxam | 0.01, 0.03, 0.1, 0.3, 1, 3, 10, 30 μM (varied by chemical and endpoint) | Human adrenocortical carcinoma cell line (H295R) and primary HUVEC cells | Aromatase activity; CYP19 expression; cell viability | Caron-Beaudoin et al. (2016)
Imidacloprid, Thiacloprid, Thiamethoxam | 0.1, 0.3, 3, 10 μM (varied by chemical and endpoint) | Human adrenocortical carcinoma cell line (H295R) and human placental choriocarcinoma cell line (BeWo) | CYP19 catalytic activity (aromatase activity); hormone production; CYP3A7 and SULT2A1 expression | Caron-Beaudoin et al. (2017)
Acetamiprid, Imidacloprid | 0.5, 5 mM | Mouse oocytes, sperm, fertilized zygotes, fertilized embryos | Sperm DNA integrity; sperm fertilization capability; embryo development; zygote development | Gu et al. (2013)
Imidacloprid | 1 nM to 0.1 mM (only IC50 reported, not specific concentrations) | Primary juvenile mouse Sertoli SC5 cells | Anti-androgenic activity; COX enzyme expression | Kugathas et al. (2016)

PC12 = pheochromocytoma; PC12D = chromaffin-cell tumor; AChE = acetylcholinesterase; GRP = glucose regulated protein; HSP = heat shock protein; HUVEC = human umbilical vein endothelial; COX = cyclooxygenase; TH = tyrosine hydroxylase; PNMT = phenylethanolamine N-methyltransferase.