# Methods

The systematic review techniques applied in this scoping review adhered to the framework developed by Office of Health Assessment and Translation (OHAT) (Rooney et al. 2014). The OHAT Systematic Review framework consists of a seven-step process; the first three are relevant to produce a scoping review, whereas the last four are relevant for assessing study quality and synthesizing evidence. Therefore, this scoping review was restricted to the first three steps: (1) problem formulation, (2) literature search and study selection, and (3) abbreviated data extraction.

## Problem Formulation

Neonicotinoid pesticides were nominated in 2014 by members of the public to the National Toxicology Program (NTP) for possible evaluation of noncancer health outcomes and exposure summary. It was unclear from the nominations and initial literature searches whether the extent or nature of the available literature was sufficient to support conclusions as to whether exposure to neonicotinoid pesticides is a hazard to human health. Therefore, as part of the problem formulation activities, NTP requested information about these pesticides on October 7, 2015, in the Federal Register and considered public comments (see https://ntp.niehs.nih.gov/go/796533). NTP learned that an ongoing systematic review activity focused on the human data was underway at George Washington University (Washington, DC). NTP partnered with Drs. Melissa Perry and Andria Cimino in their review of the epidemiological evidence to address one aspect of the nomination, which led to subsequent publication of a systematic review of the epidemiological literature on the health effects of neonicotinoids (Cimino et al. 2017).

Subsequently, NTP learned that the U.S. EPA Office of Pesticide Programs (OPP) would be evaluating currently registered neonicotinoid pesticides as part of registration review activities including risk assessments of currently registered neonicotinoid pesticides. Thus, NTP consulted with EPA to develop a scoping review protocol using the OHAT Systematic Review framework to describe the approach for the citation screen and review, and data extraction to support EPA’s registration review process (Appendix B).

### Chemical Selection

Seven chemicals were considered as members of the class of neonicotinoid pesticides that act on nicotinic acetylcholine receptors (nAChRs) (Jeschke et al. 2011). Each of these chemicals are sold under multiple product names and are listed by the percent of U.S. market share in 2009 (Jeschke et al. 2011):

- Imidacloprid ($1,091 million, 41%)
- Thiamethoxam ($672 million, 25%)
- Clothianidin ($439 million, 17%)
- Acetamiprid ($276 million, 10%)
- Thiacloprid ($112 million, 4%)
- Dinotefuran ($79 million, 3%)
- Nitenpyram ($8 million, 0.3%)

## PECO Statement

A PECO (Population, Exposure[s], Comparator[s], and Outcome[s]) statement (Table 1) was developed to address and understand the potential effects of neonicotinoid pesticides on human health-relevant effects reported in humans, animals, and in vitro model systems (Table 1). The PECO statement is used to help develop the specific research questions, search terms, and inclusion/exclusion criteria for the systematic review (Higgins and Green 2011).

Table 1 PECO (Populations, Exposures, Comparators, Outcomes) Statement

PECO Element | Evidence
[underlined: P]opulation | [underlined: Human]: All epidemiological studies [underlined: Animal]: Nonhuman animals, including studies in laboratory animals, fish, wildlife (mammalian species), domestic pets,^a^ Drosophila, and C. elegans. Studies of pesticide effects in insects (e.g., efficacy studies in target pests or off-target lethality in bees) were not considered relevant and excluded. However, studies in Drosophila were included since they were used to investigate biological mechanisms relevant to humans. [underlined: In vitro]: In vitro models utilizing organs, tissues, cell lines, or cellular components
[underlined: E]xposure | Non-acute exposure to neonicotinoid pesticides based on administered dose or concentration, biomonitoring data (e.g., urine, blood, other specimens), environmental measures (e.g., air, water levels), or job title (e.g., pesticide applicator). Acute poisonings in humans, both accidental and intentional, were not considered representative of exposures in the general population and were excluded. Relevant neonicotinoid pesticides include: Acetamiprid (CASRN 152949-80-9 or 135410-20-7) Clothianidin (CASRN 210880-92-5) Dinotefuran (CASRN 165252-70-0) Imidacloprid (CASRN 138261-41-3 or 105827-78-90) Nitenpyram (CASRN 150824-47-8) Thiacloprid (CASRN 111988-49-9) Thiamethoxam (CASRN 153719-23-4)
[underlined: C]omparator | Both experimental (controlled exposure or treatment) and observational studies (wildlife, ecological) should be included. Experimental studies should include an untreated or vehicle control.
[underlined: O]utcomes | All human health-relevant effects

CASRN = Chemical Abstract Services Registry Number.

^a^ Studies of domestic pets were considered if the health of the animal was reported (not product efficacy studies e.g., killing fleas and ticks).

## Literature Search

A broad literature search strategy was constructed for each chemical using: (1) common name of the chemical, (2) Chemical Abstract Services Registry Number (CASRN), and (3) retrieval of synonyms from the ChemIDplus database, which currently contains chemical names and synonyms for over 400,000 chemicals (ChemIDplus 2017). No limitations were applied in terms of health outcomes or study designs to retrieve any publications mentioning exposure to any of the included pesticide(s). Because this is a scoping review, a single database (PubMed) was selected that would be most likely to contain the relevant publications on health effects of neonicotinoid pesticides. Rather than a comprehensive search of a systematic review developed to reach hazard conclusions, this scoping review considered a single database sufficient because the goal was to map the major health effects categories for each evidence stream and identify major gaps in the literature and principal health effects categories that might support further evaluation by a subsequent systematic review. PubMed was most recently searched on April 10, 2018 from the beginning of the database entries (full details of the search strategy are presented in Appendix A). No publication year or language limits were imposed.

## Study Selection

### Evidence Selection Criteria

Studies were eligible for inclusion if they satisfied the eligibility criteria in the PECO statement. Inclusion and exclusion criteria used to screen articles for relevance and eligibility at both the title-and-abstract and full-text screening stages are summarized in (Table 1). The reason for exclusion at the full-text-review stage was annotated and is reported in a study flow diagram (Figure 1). A study was excluded if it: (1) was a review, commentary, or editorial with no original data; (2) lacked relevant exposure information; (3) lacked health outcome information; (4) focused only on insects (Droshophila studies were included if used as a human health model); (5) was a conference abstract, thesis/dissertation; (6) the full text was “not available”; or (7) was not available in English (although the literature search did not limit based on foreign language, for this scoping document these studies were not translated and are therefore considered excluded).

Figure 1

Study Selection Diagram

*Five publications contained data relevant to both experimental mammal studies and in vitro studies.

The reference lists of relevant, authoritative reviews or government-authored (state and federal) technical reports identified during the initial search were hand-searched to identify additional studies that were not identified through the electronic searches. These studies were evaluated using the same inclusion and exclusion criteria and processes used for screening the electronic search results. Relevant studies identified through these steps are marked as “references identified from other sources” in the study selection diagram (Figure 1).

### Screening Process

DistillerSR^®^, a web-based, systematic review software program with structured forms and procedures was used to screen articles for relevance and eligibility to ensure standardization of process.^a^ The electronic search results were loaded in EndNote and exact article duplicates were removed prior to uploading the references to DistillerSR.

a DistillerSR^®^ (http://systematic-review.net/) is a proprietary project management tool for tracking studies through the screening process and storing data extracted from these studies using user-customized forms.

#### Title/Abstract Review

Two members of the evaluation design team independently conducted a title-and-abstract screen of the search results. Studies were considered possibly relevant if they met either the PECO statement, or if evaluators were unable to determine relevance from the abstract and title. If they were considered possibly relevant, studies were moved to a full-text review. Prior to beginning screening, evaluators were provided project-specific written instructions by the project lead to improve accuracy and consistency among screeners during a pilot training phase. Initially, all articles were screened by each screener and the project lead, with a comparison and discussion of discrepancies by all screeners. On the basis of these discussions, inclusion and exclusion criteria definitions were refined for clarity. After refinement of the study screening criteria, the title and abstracts of all remaining references were reviewed by any two members of the team, with any conflicts resolved through discussion with the project lead.

#### Full-text Review

After completion of the title/abstract screen, full-text articles were retrieved for those studies that either clearly met the inclusion criteria or where eligibility to meet the inclusion criteria was unclear. Two members of the evaluation design team independently conducted a full-text screen of the search results to determine whether a reference met the inclusion criteria. The studies possibly relevant to human health effects were then tagged by the evidence stream (e.g., human, animal, or in vitro), exposure type (i.e., neonicotinoid pesticide(s) studied), and health effect category. Substantive disagreements on inclusion of the study, abstracted data or study characteristics were resolved by discussion with the project lead to reach consensus.

## Data Extraction

To develop the evidence maps for the scoping review, data extraction was limited to recording and categorizing studies in DistillerSR, Excel^®^, and Tableau^®^ by key study factors to address the research question, namely evidence stream, study type, exposure, species, and health outcome. Data extraction and categorization was performed by one member of the evaluation team and checked by a second member of the evaluation team for completeness and accuracy. After initial review of the broad health categories, additional study information was extracted for a subset of studies including details on: (1) neurological endpoints measured because neurological effect was the most often-studied health outcome across all evidence streams, and (2) congenital and developmental effects because these outcomes were the most prevalent in human studies.

### Data Availability

Interactive versions of each figure can be accessed directly using the link included beneath each figure. In addition, all interactive figures and additional study details can be viewed online and can be downloaded from Tableau in Microsoft Excel format here: https://doi.org/10.22427/NTP-DATA-002-00069-0001-0000-8 (NTP, 2019).