# Introduction

Neonicotinoid pesticides are a class of insecticides that are neurotoxic to insects through insect nicotinic acetylcholine receptors (nAChRs) (Tan et al. 2007). Because nAChRs are also present in the nervous systems of mammals, there is concern that neonicotinoids may affect animals other than their insect targets, including humans (Keil et al. 2014; USDA 2014; Van der Sluijs et al. 2015; Yang et al. 2014). Globally, seven neonicotinoid pesticides are commercially available: imidacloprid, acetamiprid, clothianidin, thiamethoxam, thiacloprid, nitenpyram, and dinotefuran (Simon-Delso et al. 2015). These pesticides have been used increasingly in U.S. agriculture since 2005 (Douglas and Tooker 2015; Jeschke et al. 2011; Simon-Delso et al. 2015) and persist in the environment, resulting in detection in the human food supply (Bonmatin et al. 2015; Chen et al. 2014; Hladik et al. 2014; USDA 2014; FDA 2016). However, no national-level exposure data (e.g., National Health and Nutrition Examination Survey) are available for these pesticides so exposure levels in the general population are unknown. Environmental persistence and irreversible binding to nAChRs have raised concerns for potential adverse human health impacts from chronic low-level exposures (Tennekes and Sanchez-Bayo 2011; Van der Sluijs et al. 2015). Although it should be noted that binding of some neonicotinoids and their metabolites to some mammalian nAChRs is relatively weak, with lower affinity and efficacy than target nAChRs (EFSA 2013).

Since their introduction in 1990, the neonicotinoid market share increased to 24% for crop protection and 80% for seed treatment by 2008 (Jeschke et al. 2011). The patent protections for these seven neonicotinoids have expired, beginning with imidacloprid in 2005; thus, the introduction of generic versions of these pesticides has broadened the markets where these pesticides are used, including in India and China (Jeschke et al. 2011). Due to widespread use, neonicotinoids were present in all streams tested near high production areas of corn and soybean in the United States; levels correlated with rain during crop planting, implicating seed treatments as the source (Hladik et al. 2014). Neonicotinoids can enter the flesh of the fruit or vegetable, making it impossible to wash and remove residues prior to consumption (Chen et al. 2014). Although below EPA tolerances, neonicotinoid pesticide residues were detectable in many fruits and vegetables tested by the U.S. Department of Agriculture in 2013 (USDA 2014), and were among the most frequently detected pesticides on human foods by the U.S. Food and Drug Administration in 2016, which monitored pesticide residues on prepared foods as part of the Pesticide Monitoring Program (FDA 2016).

Exposure to neonicotinoid pesticides has been associated with adverse health effects in various species, including humans, other mammals, honeybees, and other wildlife (Cimino et al. 2017; Krupke et al. 2012; Mason et al. 2013; Morrissey et al. 2015; Pisa et al. 2015; Rundlof et al. 2015; Van der Sluijs et al. 2015; Whitehorn et al. 2012). Several studies have characterized the potential neurotoxic effects of neonicotinoids (Kimura-Kuroda et al. 2012; Li et al. 2011). For example, nAChRs are important for synaptic transmission and learning and memory (Levin 2002), and in vitro studies using cerebellar neurons from neonatal rats suggested that neonicotinoid pesticides can affect nAChRs in a way similar to nicotine (Kimura-Kuroda et al. 2012; Tomizawa et al. 2001). Neonicotinoids can bind the α4β2 and α7 nAChR subtypes (Li et al. 2011), and perturbation of this receptor subtype is associated with various neurological effects, including depression, schizophrenia, and neurodegenerative diseases like Alzheimer’s and Parkinson’s disease (Hogg et al. 2003). In addition, the α4β2 nAChR subtype plays an important role in the developing brain, including the proliferation, migration, and differentiation of neurons and their integration into neural circuits (Dwyer et al. 2009; Role and Berg 1996). Other potential adverse health effects associated with neonicotinoid exposure include developmental and reproductive effects in mammals (Abou-Donia et al. 2008; Gu et al. 2013; Van der Sluijs et al. 2015).

The associations between neonicotinoid pesticide exposures and potential human health effects were identified as a potential candidate for systematic review. Given the interest and extent of the evidence, the National Toxicology Program (NTP) at National Institute of Environmental Health Sciences conducted this scoping review to investigate the extent of the evidence from human and nonhuman studies relevant for evaluating potential human health effects of neonicotinoid pesticides. Publicly available published health effects literature for neonicotinoid pesticides was systematically collected and categorized to develop a systematic evidence map of the key neonicotinoid pesticides (by chemical) and the related health effects, types of evidence, and gaps in research. The information and presentation of the data in this scoping review were developed to support decision-making on this topic by assessing whether the publicly available literature database is sufficient for developing hazard characterization conclusions for one or more health effects in a full systematic review or for consideration of future research on this topic.

## Objective and Specific Aims

### Objective

The objective of this scoping review was to identify and summarize the literature relevant to neonicotinoid pesticide exposure and human health effects.

### Specific Aims

- Identify literature reporting exposure(s) to one or more neonicotinoid pesticides registered for use in the United States and all outcomes relevant to human health effects, including epidemiological, experimental animal, and in vitro model systems.
- Summarize potential health effects and mechanistic data by neonicotinoid pesticide (i.e., the extent and types of health effects studies presented as interactive evidence map and accompanying narrative summary).
- Summarize evidence available on health effects with a large amount of data (e.g., neurological).