# Conflict of Interest

Individuals identified as authors in the About This Report section have certified that they have no known real or apparent conflict of interest related to neonicotinoid pesticides.