# Acknowledgments

This work was supported by the Intramural Research Program (ES103316 and ES103317) at the National Institute of Environmental Health Sciences, National Institutes of Health and performed for the National Toxicology Program, Public Health Service, U.S. Department of Health and Human Services under contracts GS00Q14OADU417 and HHSN273201600015U.