# Appendix B Supplemental Files

The following supplemental files are available at https://doi.org/10.22427/NTP-DATA-002-00069-0001-0000-8.

## B.1 Protocol Information

Protocol

## B.2 Tableau Dataset

Neonicotinoid Dataset