# References

1 Perkins AN Inayat-Hussain SH Deziel NC Johnson CH Ferguson SS Garcia-Milian R Thompson DC Vasiliou V Evaluation of potential carcinogenicity of organic chemicals in synthetic turf crumb rubber. Environ Res. 2019;169:163–172. 10.1016/j.envres.2018.10.018 30458352
2 United States Environmental Protection Agency (U.S. EPA). Federal research action plan (FRAP) on recycled tire crumb used on playing fields and playgrounds. 2016. EPA/600/R-16/364. https://www.epa.gov/sites/production/files/2016-12/documents/federal_research_action_plan_on_recycled_tire_crumb_used_on_playing_fields_and_playgrounds_status_report.pdf [Accessed: 3 Oct, 2017]
3 European Chemicals Agency (ECHA). Annex XV Report: An evaluation of the possible health risks of recycled rubber granules used as infill in synthetic turf sports fields. 2017. https://echa.europa.eu/documents/10162/13563/annex-xv_report_rubber_granules_en.pdf/dbcb4ee6-1c65-af35-7a18-f6ac1ac29fe4
4 Rijksinstituut voor Volksgezondheid en Milieu [Netherlands National Institute for Public Health and the Environment] (RIVM). Evaluation of health risks of playing sports on synthetic turf pitches with rubber granulate. 2017. Report Number: 2017-0016. https://www.rivm.nl/dsresource?objectid=a397bdf3-7aa7-490a-85bd-5992b78bcb42&type=pdf&disposition=inline
5 United States Environmental Protection Agency (U.S. EPA). Federal research on recycled tire crumb used on playing fields. U.S. Environmental Protection Agency; 2016. https://www.epa.gov/chemical-research/federal-research-recycled-tire-crumb-used-playing-fields [Accessed: 2017]
6 Agency for Toxic Substances and Disease Registry (ATSDR). Federal research action plan on recycled tire crumb used on playing fields and playgrounds. 2016. https://www.atsdr.cdc.gov/frap/index.html [Accessed: 2017]
7 Consumer Product Safety Commission (CPSC). Crumb rubber information center. 2016. https://www.cpsc.gov/Safety-Education/Safety-Education-Centers/Crumb-Rubber-Safety-Information-Center [Accessed: 2017]
8 Office of Environmental Health Hazard Assessment (OEHHA). Synthetic turf studies. 2017. https://oehha.ca.gov/risk-assessment/synthetic-turf-studies [Accessed: 2017]
9 National Toxicology Program (NTP). Synthetic turf/recycled tire crumb rubber. 2017. https://ntp.niehs.nih.gov/results/areas/syntheticturf/index.html [Accessed: 2017]
10 National Toxicology Program (NTP). NTP research report on chemical and physical characterization of crumb rubber. Research Triangle Park, NC: National Toxicology Program; 2019. Research Report 11.
11 National Toxicology Program (NTP). NTP research report on synthetic turf/recycled tire crumb rubber: Characterization of the biological activity of crumb rubber in vitro. Research Triangle Park, NC: National Toxicology Program; 2019. Research Report 12.
12 National Toxicology Program (NTP). NTP research report on synthetic turf/recycled tire crumb rubber: Feasibility study in support of non-inhalation in vivo exposures of synthetic turf/recycled tire crumb rubber. Research Triangle Park, NC: National Toxicology Program; 2019. Research Report 13.
13 National Toxicology Program (NTP). NTP research report on synthetic turf/recycled tire crumb rubber: 14-day exposure characterization studies of crumb rubber in female mice housed on mixed bedding or dosed via feed or oral gavage. Research Triangle Park, NC: National Toxicology Program; 2019. Research Report 14.
14 Bolgar MH J; Groeger, J; Meronek, S. Handbook for the Chemical Analysis of Plastic and Polymer Additives. 2nd ed. Boca Raton (FL): CRC Press; 2015. 10.1201/b19124
15 Pavilonis BT Weisel CP Buckley B Lioy PJ CP; Buckley, B; Lioy, PJ, Bioaccessibility and risk of exposure to metals and SVOCs in artificial turf field fill materials and fibers. Risk Anal. 2014;34(1):44–55. 10.1111/risa.12081 23758133
16 PerkinElmer. Compositional Analysis of Tire Elastomers Using AutoStepwise TGA. 2012.
17 Cambridge Polymer Group. CPGAN #025 Car Tire Composition Analysis by TGA-FTIR. 2014.
18 McNitt A, Petrunak D, Serensits T. Temperature amelioration of synthetic turf surfaces through irrigation. University Park, PA: The Pennsylvania State University. https://plantscience.psu.edu/research/centers/ssrc/documents/temperature-irrigation.pdf 10.17660/ActaHortic.2008.783.59 10.17660/ActaHortic.2008.783.59
19 Williams C, Pulley G. Synthetic surface heat studies. Provo, UT: Brigham Young University. https://aces.nmsu.edu/programs/turf/documents/brigham-young-study.pdf
20 AST temps and TPG temps. 2016. http://www.synturf.org/images/AST-Temps-TPG-Temps-Rev1-20161007.pdf
21 International Organization for Standardization (ISO). (International Organization for Standardization). Soil quality - Assessment of human exposure from ingestion of soil and soil material - Procedure for the estimation of the human bioaccessibility/bioavailability of metals in soil. 2016. ISO/DIS 17924:2016(E).
22 United States Environmental Protection Agency (U.S. EPA). (U.S. Environmental Protection Agency). Research Protocol: Collections Related to Synthetic Turf Fields with Crumb Rubber Infill. 2016. https://www.epa.gov/sites/production/files/2016-08/documents/tcrs_research_protocol_final_08-05-2016.pdf