# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, NC

ISSN: 2473-4756

DOI: https://doi.org/10.22427/NTP-RR-11

Report Series: NTP Research Report Series

Report Series Number: 11

Official citation: National Toxicology Program (NTP). 2019. NTP research report on the chemical and physical characterization of recycled tire crumb rubber. Research Triangle Park, NC: National Toxicology Program. Research Report 11.