# Peer Review

The draft research report, NTP Research Report on the Chemical and Physical Characterization of Recycled Tire Crumb Rubber, was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Research Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Joshua Kellogg, Ph.D.
  Postdoctoral Research Fellow
  University of North Carolina at Greensboro
  Greensboro, North Carolina, USA
- Robert J. Strife, Ph.D.
  Senior Scientist, Consultant (Retired)
  Procter & Gamble, Research and Development
  West Chester, Ohio, USA