# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Designed study, evaluated and interpreted study findings
  Suramya Waidyanatha, Ph.D.
- Designed study
  Scott Masten, Ph.D.
  Georgia Roberts, Ph.D.
- Battelle Memorial Institute, Columbus, Ohio, USA
  Conducted study, evaluated and interpreted study findings
  Timothy Cristy, B.A.