# Conclusions

A crumb rubber lot prepared by combining material from multiple commercial sources was analyzed using a variety of techniques to generate information on chemical and physical characteristics. Optical and scanning electron microscopy demonstrated that the lot consisted of a range of particle sizes (<0.1–4 mm). Data from a combination of analyses demonstrate that VOCs, SVOCs, and metals constitute a very small fraction of the crumb rubber lot. Size fractionation of crumb rubber showed that chemical profiles are fairly similar between different size fractions except the 400-mesh fraction. Bioaccessibility studies conducted in vitro to mimic various routes of exposure showed that only a few constituents present in crumb rubber are present in these extracts under the conditions used, regardless of the biofluid or the analytical method used.