# Results

## Optical Microscopy

Seven regions of a sample of the crumb rubber lot were micrographed. Micrographs from two selected regions are shown in Figure 1. The crumb rubber lot consists of irregular particles in a wide range of sizes, from approximately <0.1 to 4 mm. Particles consisting of both dark and light rubber and visible non-rubber inclusions and fibers were observed.

Figure 1

Representative Optical Micrographs of Two Crumb Rubber Regions

## Scanning Electron Microscopy and Energy Dispersive X-Ray Spectroscopy

SEM images for six individual crumb rubber grains were obtained, four of which are shown in Figure 2 as images representative of the variations between different grains. Elemental composition of the analyzed areas for six grains are given in Table 1. These data represent the elemental composition of the analyzed areas of different rubber grains and not the composition of bulk crumb rubber. The data demonstrate variability in composition between crumb rubber grains, which may have derived from different tires or different parts of the same tire. As would be expected of material consisting primarily of polymer, carbon (87.2 ± 6.6%) makes up most of the crumb rubber with much lower percentages of sulfur (3.5 ± 1.3%), zinc (3.0 ± 1.8%), and oxygen (3.5 ± 1.3%), likely derived from the sulfur and zinc oxide used in the vulcanization process. A few other elements were detected at <1% (Table 1). Elemental composition of inclusions observed in crumb rubber also was measured and identified as likely clay (aluminum silicates), calcium carbonate, and talc (magnesium silicates) based on high levels of silicon, calcium, oxygen, aluminum, and magnesium detected in these inclusions.

Figure 2

Representative Scanning Electron Micrographs of the Cut Surfaces of Four Dissected Crumb Rubber Grains

Table 1 Elemental Composition^a^ (Wt %) of Six Individual Crumb Rubber Grains by Energy Dispersive Spectroscopy

Element | %
C | 87.2 (6.6)
O | 3.5 (1.3)
Mg | 0.1 (0.1)
Al | 1.2 (2.5)
Si | 1.4 (2.2)
S | 3.5 (1.7)
Ca | 0.1 (0.2)
Ti | 0.0 (0.1)
Zn | 3.0 (1.8)

^a^ Data given are for the analyzed area of individual grains to show the composition difference between different grains and do not represent composition of the bulk crumb rubber.

## Thermogravimetric Analysis

Duplicate samples were analyzed to estimate the composition of the crumb rubber lot. Samples were heated from 30°C to 700°C in a nitrogen (inert) atmosphere and then from 700°C to 900°C in an ambient air (oxidative) atmosphere to combust any remaining organic material. According to the thermogram (Figure 3), a minimal weight loss occurs below 200°C suggesting that VOCs and SVOCs comprise a very small fraction of the crumb rubber lot. The significant weight loss up to ~400°C is likely due to extender oils such as paraffinic, naphthenic, or aromatic oils.^16,17^ The weight loss between ~400°C and ~520°C may be due to decomposition of polymers with two steps indicating likely presence of two types of polymers. The last step is combustion of any uncombusted carbon-containing material including carbon black. The residue remaining after ~800°C represents the total inorganics present in the material. Based on this assessment, the crumb rubber lot contains a very small faction of VOCs and SVOCs, approximately 25%, and extender oils; 29.9% polymeric material; 37.1% carbon black (arising likely from a combination of uncombusted material and original carbon black present in crumb rubber); and 7.7% inorganics.

Figure 3

Representative Thermogram from Thermo Gravimetric Analysis of Crumb Rubber

## Inorganics Analysis

Inorganics were determined in duplicate using ICP–MS or ICP–AES, shown in Table 2. Only zinc (1.68%), silicon (0.932%), and aluminum (0.106%) were detected above 0.1%. All other analytes were below 0.1% (Table 2). The level of chromium was below the limit of quantitation for the method.

Table 2 Estimated Levels of Metals in Crumb Rubber Lot^a^

Element | Replicate 1 | Replicate 2 | Average
Zinc | 1.62% | 1.74% | 1.68%
Silicon | 0.898% | 0.966% | 0.932%
Aluminum | 0.104% | 0.108% | 0.106%
Potassium | 473 ppm | 438 ppm | 456 ppm
Iron | 523 ppm | 340 ppm | 432 ppm
Magnesium | 367 ppm | 321 ppm | 344 ppm
Sodium | 304 ppm | 300 ppm | 302 ppm
Cobalt | 153 ppm | 136 ppm | 145 ppm
Copper | 51.6 ppm | 37.5 ppm | 44.6 ppm
Lead | 12.1 ppm | 12.9 ppm | 12.5 ppm
Nickel | 4.53 ppm | 7.32 ppm | 5.93 ppm
Manganese | 5.78 ppm | 5.99 ppm | 5.89 ppm
Barium | 4.95 ppm | 5.48 ppm | 5.22 ppm
Tin | 1.51 ppm | 2.39 ppm | 1.95 ppm
Arsenic | 0.929 ppm | 0.680 ppm | 0.805 ppm
Cadmium | 0.715 ppm | 0.582 ppm | 0.649 ppm
Chromium | <LOQ^b^ | <LOQ | <LOQ

^a^ Analyses were conducted either by ICP–MS or ICP–AES. Data are shown for duplicate analyses. Data are organized based on the levels estimated with highest shown on top.

^b^ LOQ = limit of quantitation. For chromium, LOQ was ~13 ppm.

## Headspace Gas Chromatography–Mass Spectrometry Analysis for Volatile and Semivolatile Organic Compounds

Duplicate samples of crumb rubber were analyzed using headspace GC–MS to determine VOCs and SVOCs using varying incubation temperatures. The temperatures were selected to cover a potential range of temperatures on playing fields including worst case scenarios.^18-20^ Figure 4 shows a comparison of chromatograms from ambient temperature, 50°C, and 100°C. Very few analytes were present in chromatograms incubated at ambient temperature; as the temperature increased, the number and level of constituents in chromatograms increased. For example, the approximate number of peaks increased from ~7 at ambient temperature to >150 at 100°C. Therefore, samples from 100°C incubation were selected for identifying and quantifying constituents using the conditions described under methods. Of the large number of peaks detected (~150), 33 were identified using a combination of retention times of analytical standards (targeted analysis) and library matches of mass spectra; as an example, comparison of spectra leading to identification of methyl isobutyl ketone is shown in Figure 5. The identified peaks constituted a majority (~86%) of the total peak area. The remaining peaks had low confidence library matches. Using the conditions described under methods, the estimated levels of the 33 compounds identified are given in Table 3, totaling ~0.0007% by weight in crumb rubber.

Figure 4

Comparison of GC–MS Chromatograms at Varying Incubation Temperatures in Headspace GC–MS Analysis: (A) Full Scale (B) Expanded Scale

Figure 5

GC–MS Spectra for Methyl Isobutyl Ketone: (A) Standard Spectrum, (B) Crumb Rubber Sample Spectrum, and (C) Library Spectrum

Table 3 Estimated Levels of Volatile and Semivolatile Organic Compounds in Crumb Rubber Lot by Headspace GC–MS^a^

Compound | Replicate 1 (ppm in Rubber) | Replicate 2 (ppm in Rubber) | Average (ppm in Rubber) | Match Score^b^(%)
Methyl Isobutyl Ketone | 3.48 | 3.21 | 3.35 | 98.6
Aniline | 0.980 | 1.12 | 1.05 | 99.6
Benzothiazole | 0.753 | 0.684 | 0.719 | 94.0
Toluene | 0.441 | 0.415 | 0.428 | 100.0
Cyclohexanone | 0.387 | 0.344 | 0.366 | 99.3
2,4,4-Trimethylpentene | 0.125 | 0.116 | 0.120 | 96.5
Methyl Vinyl Ketone | 0.113 | 0.0990 | 0.106 | 85.2^c^
Hexamethylcyclotrisiloxane | 0.105 | 0.0954 | 0.100 | 99.6
5-Methyl-2-hexanone | 0.0968 | 0.0773 | 0.0870 | 98.0
Phenol | 0.0758 | 0.0876 | 0.0817 | 87.0
Trichloroethylene | 0.0681 | 0.0648 | 0.0665 | 99.7
Butyraldehyde | 0.0313 | 0.0293 | 0.0303 | 26.6^c^
Hexanal | 0.0198 | 0.0180 | 0.0189 | 90.9
m/p-Xylene | 0.0171 | 0.0163 | 0.0167 | 99.1
3-Methylhexane | 0.00882 | 0.0118 | 0.0103 | 89.5
1-Methylnaphthalene | 0.00994 | 0.00814 | 0.00904 | 93.6
Naphthalene | 0.00689 | 0.00599 | 0.00644 | 99.9
Styrene | 0.00603 | 0.00661 | 0.00632 | 80.2
Furfural | 0.00516 | 0.00561 | 0.00539 | 52.7^c^
1,2,4-Trimethylbenzene | 0.00577 | 0.00483 | 0.00520 | 83.6
2-Methylnaphthalene | 0.00535 | 0.00487 | 0.00511 | 88.8
Ethanol | 0.00451 | 0.00538 | 0.00495 | 99.6
Pentadecane | 0.00410 | 0.00497 | 0.00454 | 64.8^d^
Decane | 0.00394 | 0.00360 | 0.00377 | 58.8^d^
Tetradecane | 0.00379 | 0.00364 | 0.00371 | 74.4^d^
Butylated Hydroxytoluene | 0.00294 | 0.00205 | 0.00250 | 84.6
Tridecane | 0.00198 | 0.00166 | 0.00182 | 63.7^d^
3-Ethyltoluene | 0.00141 | 0.00130 | 0.00135 | 87.7
t-Butylamine | 0.00147 | 0.00118 | 0.00132 | 99.5
o-Xylene | 0.00115 | 0.00131 | 0.00123 | 68.4^c^
Ethylbenzene | 0.00118 | 0.00098 | 0.00108 | 83.1
Acetone | 0.000502 | 0.000495 | 0.000499 | 98.6
Heptane | 0.000249 | 0.000207 | 0.000228 | 96.4

^a^ The data presented are following incubation at 100 °C and under conditions described in methods.

^b^ The compounds in this table were identified by matching retention time and mass spectra with standards. The match score with a library spectrum is included as a confirmation.

^c^ The match score with the library spectrum was low because the peak in the sample was poorly resolved from neighboring peaks and its mass spectrum contained fragments contributed by those peaks.

^d^ For the larger alkanes, the response in the samples was too low to detect the low abundance of higher mass fragments, but the peak did match retention time and lower mass fragments with the corresponding standard.

## Gas Chromatography–Mass Spectrometry Analysis of Solvent-Extractable Constituents Fraction

Duplicate samples of the crumb rubber were extracted with different solvents across the polarity range from water to hexane. The average estimated extractable material, expressed as a percentage, is given in Table 4. Ethyl acetate, methylene chloride, hexane, and carbon disulfide yielded similar amounts of extractable material, and ethanol extracted approximately half as much material. Using water as the solvent yielded less than 1%. This observation indicates most extractable materials from crumb rubber are relatively non-polar organic compounds.

Table 4 Percent of Extractable Crumb Rubber in Various Solvents^a^

Solvent | Average (%)
Water | 0.60
Ethanol | 4.19
Ethyl Acetate | 7.21
Hexane | 7.39
Methylene Chloride | 7.98
Carbon Disulfide | 8.35

^a^ The amount extracted by solvent under the conditions described in the method was calculated by subtracting the weight of the dried residual crumb rubber from the starting crumb rubber weight. The percent extracted was calculated by dividing the extracted weight by the starting crumb rubber weight.

All samples were analyzed by GC–MS, the chromatograms for which are given in Figure 6 including for blank solvents. Under these conditions, the pattern of profiles is similar except for the water extract, where very few discernible peaks were observed (Figure 7). No peaks were detected in corresponding solvent blanks (data not shown).

Figure 6

Comparison of GC–MS Chromatograms of Crumb Rubber Following Extraction with Various Solvents: (A) Full- and (B) Expanded-Scale Chromatograms, and (C) Blank Solvents

Figure 7

GC–MS Chromatogram of Crumb Rubber Following Extraction with Water

The chromatogram for the methylene chloride extract was selected for identification of peaks using the criteria given under methods. Compounds identified with high confidence are presented in Table 5. To qualify for high confidence identification, the peak in the extract had to have either a matching retention time and mass spectrum of a standard or a >85% match with a library reference spectrum, or both. As an example, comparison of spectra leading to identification of n-(1,3-dimethylbutyl)-n'-phenyl-p-phenylenediamine (6PPD) is shown in Figure 8. Compounds that did not meet the criteria for the first category were assigned medium confidence. For these compounds, matching retention time and mass spectrum with a standard was difficult due to co-eluting or small peaks, or the match with the library spectrum was lower (30–84%); these data are presented in Appendix C, Table C-1. In cases of multiple, very similar isomers (such as the xylenes), standards would be required to determine which isomers might be present. Appendix C, Table C-2 lists potential crumb rubber constituents based on the literature (Appendix A), which were investigated but not found in the current lot under these instrumental and test conditions.

Table 5 Constituents of Crumb Rubber in Methylene Chloride Extract Identified by GC–MS with High Confidence^a^

Name | CAS Number | ID by Match with Standard^a^ | ID by Match with Library^b^
Naphthalene | 91-20-3 | Yes | Yes
Acenaphthene | 83-32-9 | Yes | Yes
Phenanthrene | 65996-93-2 | Yes | Yes
Fluoranthene | 206-44-0 | Yes | Yes
Pyrene | 129-00-0 | Yes | Yes
2-Methylnaphthalene | 91-57-6 | No | Yes
1-Methylnaphthalene | 90-12-0 | No | Yes
1,2-Dihydro-2,2,4-trimethylquinoline | 147-47-7 | No | Yes
Benzothiazole | 95-16-9 | Yes | Yes
Butylated Hydroxytoluene | 128-37-0 | Yes | Yes
4-Tert-octylphenol | 140-66-9 | Yes | Yes
Heptadecane | 629-78-7 | Yes | Yes
Octadecane | 593-45-3 | Yes | Yes
Nonadecane | 629-92-5 | Yes | Yes
Icosane | 112-95-8 | Yes | Yes
Heneicosane | 629-94-7 | Yes | Yes
Docosane | 629-97-0 | Yes | Yes
Tricosane | 638-67-5 | Yes | Yes
Tetracosane | 646-31-1 | Yes | Yes
Pentacosane | 629-99-2 | Yes | Yes
Hexacosane | 630-01-3 | Yes | Yes
Heptacosane | 593-49-7 | Yes | Yes
Octacosane | 630-02-4 | Yes | Yes
Nonacosane | 630-03-5 | Yes | Yes
Triacontane | 638-68-6 | Yes | Yes
Hentriacontane | 630-04-6 | No | Yes
Dotriacontane | 544-85-4 | No | Yes
Tritriacontane | 630-05-7 | No | Yes
Pentatriacontane | 630-07-9 | No | Yes
Phthalimide | 85-41-6 | Yes | Yes
Cyclopropyl Methyl Ketone | 765-43-5 | Yes | Yes
Toluene | 108-88-3 | Yes | Yes
4-Methyl-2-pentanone (MIBK) | 108-10-1 | No | Yes
n-(1,3-Dimethylbutyl)-n'-phenyl-p-phenylenediamine (6PPD) | 793-24-8 | Yes | Yes
N-Isopropyl-N'-phenyl-p-phenylenediamine (IPPD) | 101-72-4 | No | Yes
3,5-Di-tert-butyl-4-hydroxybenzaldehyde | 1620-98-0 | No | Yes
Methyl Stearate | 112-61-8 | No | Yes
Bis(2-ethylhexyl) Phthalate | 117-81-7 | Yes | Yes
Cyclopentanone, 2-Methyl- | 1120-72-5 | No | Yes
Trichloroethane | 71-55-6/79-00-5 | No | Yes
1-Hexene, 3,5,5-Trimethyl- | 4316-65-8 | No | Yes
3-[(E)-2-(4-Hexoxyphenyl)ethenyl]phenol | Unknown | No | Yes

^a^ Identification of constituents was done with retention time and mass spectral match with a standard, a >85% match, or both with a library reference spectrum.

^b^ ≥85% match with a library spectrum.

Figure 8

GC–MS Spectra for the n-(1,3-Dimethylbutyl)-N'-phenyl-p-phenylenediamine (6PPD): (A) Standard Spectrum, (B) Crumb Rubber Sample Spectrum, and (C) Library Spectrum

## Liquid Chromatography–Mass Spectrometry Analysis of Solvent-Extractable Constituents Fraction

Ethanol extract was analyzed by LC–MS using positive and negative ion modes of ESI and APCI sources. The APCI source resulted in better ionization and detection of more peaks. Similarly, positive ionization resulted in more peaks. Because extensive investigation was conducted using GC and the LC profiles had fewer peaks, only the chromatograms from APCI positive ion mode were used for analyte identification (although this may have limited the identification of unique compounds that ionize only in negative ion mode). Total ion chromatograms following analyses of samples by positive and negative ion modes are shown in Figure 9. The blank ethanol chromatograms were subtracted from the sample chromatograms to produce the blank-subtracted total ion chromatograms. A list of analytes identified under the conditions mentioned above is given in Table 6.

Figure 9

LC–MS Total Ion Chromatograms of Ethanol Extract of Crumb Rubber: Comparison of Blank-Subtracted Extract of Crumb Rubber, (A) Positive Ion Mode and (B) Negative Ion Mode

Table 6 Constituents of Crumb Rubber in Ethanolic Extract Identified by LC–MS

Retention Time (Minutes) | Name | CAS No. | Basis for Identification
21.6 | Benzothiazole | 95-16-9 | Retention time and mass spectrum match with a standard and a library spectrum.
29.7 | n-(1,3-Dimethylbutyl)-n'-phenyl-p-phenylenediamine (6PPD) | 793-24-8 | Retention time and mass spectrum match with a standard.
19.8 | 2-Hydroxybenzothiazole | 934-34-9 | Mass spectrum match with a library spectrum. Seen in crumb rubber in the literature.
22.5 | Hexa(methoxymethyl)melamine | 68002-20-0 | Mass spectrum match with a library spectrum. Seen in crumb rubber in the literature.

The largest peak observed in both the positive and negative ion modes (29.7 minutes) the matched retention time and mass spectrum with the standard for 6PPD, which was also the largest peak observed in the GC–MS analysis of solvent extracts. The 21.6-minute peak matched retention time and mass spectrum with the standard for benzothiazole, which was also one of the major peaks observed in the volatiles analysis. The Massbank library identified the 19.8-minute peak as 2-hydroxybenzothiazole and the 22.5-minute peak as hexa(methoxymethyl)melamine. Several remaining unknown peaks matched molecular weight with either previously observed crumb rubber constituents or known polymer additives, but library spectra were not available and standards for those compounds had not been included in the analysis, so their identities could not be confirmed.

## Gas Chromatography–Mass Spectrometry Analysis of Crumb Rubber Fractions

Duplicate samples of crumb rubber from different mesh sizes were analyzed along with the bulk material to determine differences, if any, between different mesh sizes. Figure 10 shows a comparison of chromatographic profiles between samples; duplicates were similar and hence the chromatogram from only one replicate is shown in the figure. In general, the pattern of profiles was similar in each sample. Visually, most of the peaks show little or no change except the peak at 26.60 minutes, which was identified as toluene. As the particle size decreases, the intensity of toluene peak increases, with the 400-mesh fraction showing a significantly elevated peak compared to the unsieved bulk crumb rubber.

Figure 10

Comparison of Headspace GC–MS Chromatograms of Various Crumb Rubber Fractions and Unsieved Bulk Material Following Incubation at 100°C: (A) Full- and (B) Expanded-Scale Chromatograms

Spectral data from samples were compared to each other using multivariate statistics. Each peak in chromatogram is associated with a mass-to-charge ratio, retention time, fold change between different samples, p-value, and relative intensity. A cloud plot, which is a visualization of this multidimensional data to facilitate compound identification and data interpretation, identifying 177 significantly different spectral features is shown in Figure 11. The cloud plot shows all chromatograms overlaid along the x-axis based on the retention time and red circles at each mass-to-charge ratio (y-axis) that met the significance criteria (with size of the circle showing the relative difference between the samples). Because the mass spectrum of each compound contains multiple fragments, it is possible to have several circles over one chromatographic peak (for example, as seen for the toluene peak labeled 4 on the plot). Upon closer examination of the data, a significant number of these features were found to arise from changes in levels of toluene and methyl isobutyl ketone in these fractions (Figure 11). Although several small peaks such as xylenes also met the criteria for significance, the large cyclohexane and benzothiazole peaks did not. Other small peaks that also met the criteria for significance included 2,4,4,-trimethylpentene (~19.5 minutes), naphthalene (~51.5 minutes), methyl vinyl ketone (~16.1 minutes), and acetone (~10.5 minutes) (Figure 11).

Figure 11

Cloud Plot of GC–MS Non-Targeted Data Showing 177 Significantly Different Features Between Various Crumb Rubber Fractions

Each peak in the chromatogram is associated with a mass-to-charge ratio, retention time, fold change between different samples, p-value, and relative intensity. A cloud plot, which is a visualization of this multidimensional data to facilitate compound identification and data interpretation, identifying 177 significantly different spectral features is shown. The cloud plot shows all chromatograms overlaid along the x-axis based on the retention time and red circles at each mass-to-charge ratio (y-axis) that met the significance criteria (with size of the circle showing the relative difference between the samples).

PCA score plots, generated using the features described above from mass fragments, are shown in Figure 12A. This analysis shows that the 14-mesh and 40-mesh fractions were similar to the bulk crumb rubber lot; the pooled 14- to 80-mesh fraction was less similar to the bulk lot, likely due to inclusion of the 80-mesh fraction. Individual 80-mesh samples were not analyzed due to limitation in available material. The 400-mesh fraction differed markedly from the bulk lot and all other mesh sizes analyzed. As mentioned above, this difference between the bulk lot and mesh sizes likely stems from the changes in levels of toluene and methyl isobutyl ketone in these fractions. Because using mass fragments potentially overemphasizes the contribution from compounds such as toluene and methyl isobutyl ketone that have multiple fragments, the PCA analysis also was performed using peaks in the chromatographic profiles (Figure 12B). The outcome was similar, with the 400-mesh differing from the others.

Figure 12

Principal Component Analysis Scores Plots of GC–MS Non-Targeted Data Comparing Various Crumb Rubber Fractions: (A) Using Mass Fragments (177 Features) and (B) Using Individual Peaks

Individual data point reflects a single sample.

Hierarchical cluster analysis was conducted on individual replicates using Ward’s method; the corresponding dendrogram is shown in Figure 13. The replicates for each sample were closest to each other, demonstrating the reproducibility in sample analysis. For the different mesh-size fractions, all except the 400-mesh fraction fell in one branch of the dendrogram. The unsieved material and 14-mesh fraction clustered, and the 40-mesh and pooled 14- to 80-mesh fractions clustered.

Figure 13

Hierarchical Cluster Analysis of GC–MS Non-Targeted Data Comparing Various Crumb Rubber Fractions Using Individual Peaks

Data from individual replicates are shown.

In conclusion, GC–MS data show differences between the bulk and sieved materials. The unsieved, 14-mesh, 40-mesh, and pooled 14- to 80-mesh fractions are more similar to each other than any of them are to the 400-mesh fraction.

Concentrations of selected VOCs and SVOCs, based on those estimated previously in the bulk crumb rubber lot, were estimated for different mesh fractions, under the experimental conditions described. The estimated values are shown in Table 7 along with the bulk crumb rubber. Percent change observed for different size fractions with respect to the bulk sample was estimated as shown in Table 7. Toluene showed the greatest differences between the fractions, with the amount increasing as particle size decreased. The 400-mesh fraction contained 15 times as much toluene as the unsieved material. The second largest relative difference was with hexanal, where the 400-mesh sample had 2.5 times as much as the unsieved material. Benzothiazole and cyclohexanone, although some of the largest constituents, showed relatively little difference (<25%) between the samples.

Table 7 Average Estimated Levels of Volatile and Semivolatile Organic Compounds in Various Crumb Rubber Fractions by Headspace GC–MS

Compound | Bulk Lot^a^ | Pooled 14–80-Mesh (ppm) | 14-Mesh^b^ (ppm) | 40-Mesh (ppm) | 400-Mesh (ppm)
Methyl Isobutyl Ketone | 4.34 | 3.50 | 4.05 | 3.54 | 2.73
Toluene | 0.454 | 0.218 | 0.875 | 1.12 | 6.80
Aniline | 1.28 | 0.689 | 1.04 | 1.22 | 2.00
Benzothiazole | 0.629 | 0.474 | 0.615 | 0.633 | 0.563
Cyclohexanone | 0.464 | 0.361 | 0.438 | 0.422 | 0.347
Diphenylamine | 0.0502 | 0.0343 | 0.0667 | 0.0606 | 0.0280
2,4,4-Trimethylpentene | 0.0779 | 0.0470 | 0.0699 | 0.0537 | 0.0363
Hexamethylcyclotrisiloxane | 0.207 | 0.125 | 0.179 | 0.144 | 0.133
5-Methyl-2-hexanone | 0.330 | 0.201 | 0.274 | 0.265 | 0.139
Phenol | 0.0696 | 0.0196 | 0.0367 | 0.0315 | 0.0311
Hexanal | 0.128 | 0.0830 | 0.119 | 0.100 | 0.316
m/p-Xylene | 0.0795 | 0.0566 | 0.0703 | 0.0615 | 0.0256
1-Methylnaphthalene | 0.00352 | 0.00219 | 0.00313 | 0.00311 | 0.00139
Napthalene | 0.0121 | 0.00727 | 0.0104 | 0.00923 | 0.00531
1,2,4-Trimethylbenzene | 0.0150 | 0.00993 | 0.0124 | 0.0116 | 0.00210
2-Methylnaphthalene | 0.00598 | 0.00408 | 0.00539 | 0.00514 | 0.00289
Butylated Hydroxytoluene | 0.00298 | 0.00123 | 0.00314 | 0.00178 | 0.000503
Ethylbenzene | 0.00423 | 0.00280 | 0.00389 | 0.00338 | 0.00242
Styrene | 0.0169 | 0.0129 | 0.0192 | 0.0160 | 0.0126
3-Ethyltoluene | 0.00390 | 0.00231 | 0.00335 | 0.00315 | 0.000279

^a^ The bulk lot values were obtained in a different analysis using slightly different methodology and the duplicate samples analyzed differed by as much as 30%, so differences between samples of less than 2× are unlikely to be significant.

^b^ The mesh size is the size sieve the crumb rubber was collected on, so the samples contain particles between the mesh size of the sieve above it in the stack and the mesh size of the sieve that the material did not go through. The 14-mesh sample (the largest sieve used) contained all of the particles larger than 1.41 mm. The 40-mesh sample contained the particles between 0.420 mm and 1.41 mm. The 80-mesh sample (not analyzed) contained particles between 0.177 and 0.420 mm. The 400-mesh sample contained particles between 0.037 mm and 0.177 mm. The pooled 14- to 80-mesh sample would, therefore, contain all particles greater than 0.177 mm.

## Energy Dispersive X-Ray Spectroscopy of Crumb Rubber Fractions

The weight percent of the elements detected in the two fractions are given in Table 8. The composition of elements between the fractions, in general, are similar to each other and consistent with the data observed for the bulk material (Table 1).

Table 8 Elemental Composition (Wt %) of Crumb Rubber Fractions by Energy Dispersive Spectroscopy^a^

Element | Lot CRM12052016^b^ | Lot CRM09132016^c^
C | 80.0 (5.2) | 81.9 (1.9)
O | 10.5 (1.1) | 9.67 (1.86)
Mg | 0.14 (0.06) | 0.16 (0.07)
Al | 0.39 (0.65) | 0.11 (0.15)
Si | 3.60 (5.22) | 0.17 (0.15)
S | 2.53 (0.67) | 3.90 (1.21)
Cl | 0.26 (0.30) | 0.33 (0.13)
Ca | 0.35 (0.64) | 0.07 (0.08)
Ti | 0.01 (0.02) | 0.00 (0.01)
Zn | 2.23 (1.21) | 3.64 (1.71)

^a^ Average (standard deviation) for 10 particles is shown.

^b^ Crumb rubber lot made from combined mesh sizes 14, 40, and 80.

^c^ Crumb rubber lot made from mesh size 400.

## Bioaccessibility In Vitro

During development of a method, crumb rubber was extracted using simulated biofluids from ISO Method 17294^21^ (which is based the Bioaccessibility Research Group of Europe Unified Bioacessibility Method) and Pavilonis et al. (2016).^15^ The ISO method biofluids, which were more complex mixtures, were found to have much higher background interferences with common crumb rubber constituents than the simpler biofluid formulation used by Pavilonis et al (2016).^15^ The EPA proposed simulated biofluids^22^ are even more complex than the ISO method; for example, the gastric fluid alone contains 37 ingredients and hence was expected to have similar or higher background interferences. Hence, the Pavilonis et al. (2016)^15^ method, which has a simpler formula, was used in the current assessment.

Chromatograms of combined SIM ions for the headspace GC–MS, liquid injection GC–MS, and LC–MS from simulated ingestion fluid samples, and corresponding blanks are shown respectively, in Figure 14, Figure 15, and Figure 16 as examples. SIM ion Sets 1 through 3 denote multiple injections needed to cover multiple SIM ions as described in methods.

Figure 14

Headspace GC–MS Chromatograms at 100°C Incubation for Crumb Rubber Extracts Using Simulated Ingestion Fluid Extract and Corresponding Method Blanks

Due to the large number of analytes, each sample was injected three times with a subset of analytes in each run.

Figure 15

GC–MS Liquid Injection Chromatograms for Crumb Rubber Extracts Using Simulated Ingestion Fluid Extract and Corresponding Method Blanks

To keep the mass spectrometer cycle time short enough to generate a sufficient number of data points to improve sensitivity, the samples and blanks were injected three times, each time with a different set of SIM ions monitored (SIM ion Sets 1 to 3) as shown in the figure.

Figure 16

LC–MS Chromatograms for Crumb Rubber Extracts Using Simulated Ingestion Fluid Extract and Corresponding Method Blank

Due to its high carbon black composition, crumb rubber can act as a sorbent, in addition to leaching its own constituents. In many of the simulated biofluids, this phenomenon is evident, as many of the peaks in the blank biofluids are reduced or eliminated in the crumb rubber extracts. The method blanks had small background peaks (generally less than 10 ng/mL) for many of the compounds, so the detection limit for this analysis was set to three times the response in the blanks. The concentrations of the analytes observed in the blanks (calculated as equivalent µg/g in the crumb rubber based on the amount of crumb rubber extracted and volume of the extracts) are shown in Table 9. Any results for the samples where the blanks contained a large background (greater than 20 ng/mL) were marked with an I (for interference) in the results tables (calculated values for the samples are shown only if the sample response was at least three times that of interference peak). More of the peaks in the liquid injection GC–MS and the LC–MS analyses showed interference than in the headspace GC–MS.

Table 9 Estimated Blank Biofluid Concentration (Equivalent μg in Extract per g of Crumb Rubber Extracted)^a^

Simulated Fluid Analytical Technique | Dermal GC–MS Headspace | Dermal GC–MS Liquid | Dermal LC–MS | Inhalation GC–MS Headspace | Inhalation GC–MS Liquid | Inhalation LC–MS | Gastric GC–MS Headspace | Gastric GC–MS Liquid | GastricLC–MS | Ingestion GC–MS Headspace | Ingestion GC–MS Liquid | Ingestion LC–MS
2,4,4-Trimethylpentene | 0.368 | 0.00590 | – | 0.625 | 0.0141 | – | 0.483 | 0.00627 | – | 0.717 | 0.0360 | –
Ethylbenzene | 0.00192 | 0.108 | – | 0.00142 | 0.122 | – | 0.00191 | 0.0286 | – | 0.00238 | 0.124 | –
1,2,4-Trimethylbenzene | 0.00367 | 0.0218 | – | 0.00442 | 0.0253 | – | 0.00310 | 0.0124 | – | 0.00506 | 0.0404 | –
Aniline | 0.475 | 0.0159 | – | 0.408 | 0.0273 | – | 0.411 | 0.0469 | – | 0.789 | 0.0937 | –
Naphthalene | 0.00604 | 0.0569 | – | 0.00254 | 0.0629 | – | 0.00274 | 0.0226 | – | 0.00573 | 0.0649 | –
1-Methylnaphthalene | 0.00451 | 0.0195 | – | 0.00130 | 0.0207 | – | 0.00100 | 0.00730 | – | 0.00249 | 0.0291 | –
BHT | 0.00815 | 0.0830 | 0.576 | 0.00355 | 0.164 | 0.585 | 0.00275 | 0.129 | 0.125 | 0.00509 | 0.234 | 1.20
2-Mercaptobenzothiazole | – | 1.70 | 0.00364 | – | 1.12 | 0.00151 | – | 0.222 | 0.00290 | – | 11.2 | 0.00557
Pyrene | – | 0.168 | 0.102 | – | 0.291 | 0.0331 | – | 0.0166 | 0.135 | – | 0.187 | 0.323
Bis-2-ethylhexylphthalate | – | ND | 1.11 | – | ND | ND | – | ND | 4.09 | – | ND | 1.29
Toluene | 0.0458 | ND | – | 0.0327 | ND | – | 0.0440 | 16.1 | – | 0.477 | ND | –
Hexamethylcyclotrisiloxane | 2.69 | 3.91 | – | 3.24 | 3.65 | – | 3.29 | 3.87 | – | 3.80 | 6.68 | –
m-Xylene | 0.00568 | 0.0360 | – | 0.00350 | 0.0558 | – | 0.00497 | 0.0357 | – | 0.00754 | 0.107 | –
Styrene | 0.00389 | 0.446 | – | 0.00194 | 0.481 | – | 0.0323 | 0.205 | – | 0.00729 | 0.667 | –
3-Ethyltoluene | ND | 0.0243 | – | ND | 0.0327 | – | ND | 0.0157 | – | ND | 0.134 | –
Benzothiazole | 0.216 | 69.1 | ND | 0.129 | 63.7 | ND | 0.137 | 29.0 | 38.1 | 0.186 | 69.9 | 0.853
Dicyclohexylamine | – | ND | 0.322 | – | ND | 0.266 | – | 0.0908 | 59.4 | – | ND | 23.5
Diphenylamine | 0.0364 | 0.0987 | 0.546 | 0.0154 | 0.136 | 0.211 | 0.0309 | 0.0193 | 0.142 | 0.0739 | 0.132 | 0.509
4-Tert-octylphenol | – | ND | – | – | ND | – | – | ND | – | – | ND | –
6PPD | – | 0.336 | ND | – | 0.973 | ND | – | ND | ND | – | 0.254 | ND
Bisphenol P | – | 3.86 | 0.883 | – | 2.42 | 1.61 | – | ND | 1.45 | – | ND | 6.68
MIBK | 0.0977 | 0.0383 | – | 0.0567 | ND | – | 0.0814 | ND | – | 0.232 | 0.0478 | –
Hexanal | 0.520 | 0.253 | – | 0.557 | 1.71 | – | 1.19 | 0.238 | – | 2.34 | 0.320 | –
Cyclohexanone | 0.402 | 3.44 | ND | 0.457 | 3.53 | ND | 0.699 | 4.38 | 1.02 | 6.73 | 5.06 | ND
5-Methyl-2-hexanone | ND | 0.0150 | – | ND | 0.0211 | – | ND | 0.00700 | – | ND | 0.00506 | –
Phenol | 11.5 | 0.699 | – | 46.4 | 1.14 | – | 28.9 | 0.796 | – | 68.5 | 0.991 | –
2-Methylnaphthalene | 0.00564 | 0.0262 | – | 0.00902 | 0.0293 | – | 0.00241 | 0.0232 | – | 0.0134 | 0.0339 | –
Phthalimide | – | 2.53 | 0.876 | – | 2.00 | 0.214 | – | 2.72 | 279 | – | 2.73 | 31.9
Fluorene | 0.00158 | 0.0608 | ND | 0.00114 | 0.0602 | ND | ND | 0.0216 | ND | 0.00165 | 0.0584 | ND
2-Hydroxybenzothiazole | – | 10.8 | 0.00454 | – | 12.3 | ND | – | 12.1 | 0.0975 | – | 9.12 | 0.0628
Tetracosane | – | 30.0 | ND | – | 40.7 | 0.421 | – | 7.82 | ND | – | 25.0 | ND
Tetratriacontane | – | 13.5 | – | – | 39.4 | – | – | 7.68 | – | – | 13.2 | –

^a^ Data shown are those estimated under different experimental conditions used as described under methods.

^b^ ND = No peak detected; – = Standard not seen on this method.

The peaks identified and corresponding estimated concentration in simulated biofluids using each technique are shown in Table 10. Overall, a limited number of constituents present in crumb rubber were observed in these extracts, regardless of the biofluid or the analytical method used. In addition, hexa(methoxymethyl)melamine was identified by LC–MS in the simulated inhalation extract by library match (~80% match), but no standard was available to confirm the identity.

Table 10 Estimated Bioaccessible Constituent Concentration (μg in Extract per g of Crumb Rubber Extracted)^a^

Simulated Fluid Analytical Technique | Dermal GC–MS Headspace | Dermal GC–MS Liquid | Dermal LC–MS | Inhalation GC–MS Headspace | Inhalation GC–MS Liquid | Inhalation LC–MS | Gastric GC–MS Headspace | Gastric GC–MS Liquid | Gastric LC–MS | Ingestion GC–MS Headspace | Ingestion GC–MS Liquid | Ingestion LC–MS
2,4,4-Trimethylpentene | ND^b^ | ND | – | ND | ND | – | ND | ND | – | ND | ND | –
Ethylbenzene | ND | ND | – | ND | ND | – | ND | ND | – | ND | ND | –
1,2,4-Trimethylbenzene | ND | ND | – | ND | ND | – | ND | 0.0772 I | – | ND | ND | –
Aniline | 4.23 I | 2.80 | – | 14.1 | 2.07 | – | 1.54 I | 1.06 | – | 56.0 | 39.2 | –
Naphthalene | ND | ND | – | ND | ND | – | ND | ND | – | ND | ND | –
1-Methylnaphthalene | ND | ND | – | ND | ND | – | ND | 0.0386 I | – | ND | ND | –
BHT | ND | ND | ND | ND | ND | ND | ND | ND | 0.727 I | 0.0254 I | ND | ND
2-Mercaptobenzothiazole | – | 11.0 I | ND | – | 17.6 | 0.503 | – | 55.0 | 5.51 | – | 41.2 I | 0.615
Pyrene | – | ND | ND | – | ND | ND | – | ND | ND | – | ND | ND
Bis-2-ethylhexylphthalate | – | ND | NDI | – | ND | 1.90 | – | ND | ND | – | ND | ND
Toluene | 0.246 I | ND | – | 0.278 I | 2.17 | – | 0.362 I | NDI | – | ND | 3.77 | –
Hexamethylcyclotrisiloxane | NDI | NDI | – | NDI | NDI | – | NDI | NDI | – | NDI | NDI | –
m-Xylene | ND | ND | – | ND | ND | – | ND | ND | – | ND | ND | –
Styrene | ND | ND | – | ND | ND | – | ND | ND | – | ND | ND | –
3-Ethyltoluene | ND | ND | – | ND | ND | – | ND | ND | – | ND | ND | –
Benzothiazole | 14.5 | NDI | 34.7 | 29.6 | NDI | 77.9 | 26.6 | NDI | 380 I | 27.8 | NDI | 171
Dicyclohexylamine | – | ND | 47.4 | – | 18.7 | 218 | – | ND | 387 I | – | 7.26 | 385
Diphenylamine | ND | ND | ND | ND | ND | ND | ND | ND | ND | ND | ND | ND
4-tert-Octylphenol | – | ND | – | – | ND | – | – | ND | – | – | ND | –
6PPD | – | ND | ND | – | ND | ND | – | 26.3 | ND | – | 1.79 I | ND
Bisphenol P | – | NDI | ND | – | NDI | NDI | – | ND | NDI | – | ND | NDI
MIBK | 22.0 | 2.83 | – | 8.52 | 3.40 | – | 0.496 I | 3.28 | – | 1.63 I | 2.32 | –
Hexanal | ND | ND | – | ND | NDI | – | NDI | ND | – | NDI | ND | –
Cyclohexanone | 6.09 | NDI | ND | 3.91 I | NDI | ND | 11.4 | NDI | NDI | NDI | NDI | 12.2
5-Methyl-2-Hexanone | 0.328 | 0.0974 I | – | 0.117 | 0.118 I | – | ND | 0.121 | – | ND | 0.0939 | –
Phenol | NDI | ND | – | NDI | NDI | – | NDI | ND | – | NDI | ND | –
2-Methylnaphthalene | ND | ND | – | ND | ND | – | ND | ND | – | ND | ND | –
Phthalimide | – | 18.1 I | 5.46 | – | 6.46 I | ND | – | 19.9 I | NDI | – | 17.7 I | NDI
Fluorene | ND | ND | ND | ND | ND | ND | ND | ND | 0.491 | ND | ND | 0.981
2-Hydroxybenzothiazole | – | NDI | 3.12 | – | NDI | 118 | – | NDI | 137 | – | NDI | 1510
Tetracosane | – | NDI | ND | – | NDI | ND | – | NDI | 1.03 | – | NDI | 65.8
Tetratriacontane | – | NDI | – | – | NDI | – | – | NDI | – | – | NDI | –

^a^ Data shown are those estimated under different experimental conditions used as described under methods.

^b^ ND = <3 × blank and blank response small (<20 ng/mL); NDI = <3 × blank and blank response large (>20 ng/mL); Number and I = >3 × blank but blank response large (>10% on Sample Response); – = Standard not seen on this method.