# Materials and Methods

## Materials

Three lots of fresh crumb rubber, two from one facility manufactured by an ambient or a cryogenic process and one from one facility manufactured by an ambient process were received in multiple 1-L glass jars via OEHHA. First, the material from one facility and one type of processing was combined to produce three individual lots representing each original lot; each lot was approximately 5 kg. Subsequently, all material was combined into one homogeneous lot. All equipment and containers used during handling were cleaned with ASTM Type 1 water and dried in an oven at 150°C before use. The homogenized material was assigned lot number CRM06092016, repackaged into 1-L amber glass bottles with Teflon-lined lids, and stored in the refrigerator.

Individual and mixtures of standards of potential crumb rubber constituents were procured from Alpha Aeser (Ward Hill, MA), Sigma-Aldrich (Milwaukee, WI) or Spex Certiprep, Metuchen, NJ (Appendix A).

## Optical Microscopy

Optical micrographs of crumb rubber were obtained using an Olympus SZX12 stereo microscope with an Olympus DP-71 camera (Tokyo, Japan). The software used was PAX-it! (MIS, Villa Park, IL, version 8.0.0). A sample of crumb rubber was obtained from the bulk lot. Seven regions of this sample were micrographed to determine variations in size and coloration.

## Scanning Electron Microscopy and Energy Dispersive X-Ray Spectroscopy

Selected crumb rubber grains were cut with a clean razor blade to generate a flat surface required for this analysis and to expose the interior surface and any inclusions in rubber grains. The cut grains were mounted onto carbon tabs with the cut surfaces up, and the mounts were lightly coated with Au-Pd target. The mounts were examined using a JEOL 7600-F (JOEL, Tokyo, Japan) scanning electron microscope (SEM), and images were obtained using secondary and back-scattered electrons. Elemental analysis of the crumb rubber mounts, including inclusions, was obtained by energy dispersive spectroscopy (EDS) using an Apollo X silicon drift detector (EDAX, Mahwah, NJ). Spectra of six particles were analyzed and weight percent of the elements detected was estimated.

## Thermogravimetric Analysis

The crumb rubber (~18 mg per analysis) was analyzed in duplicate on a Pyris 1 (PerkinElmer, Waltham, MA) thermal gravimetric analyzer with software package v. 11.0.3.0470. Samples were heated from 30°C to 700°C in a nitrogen (inert) atmosphere and then from 700°C to 900°C in an air (oxidative) atmosphere to combust any remaining organic material. The temperature was increased at a rate of 20°C per minute. An auto stepwise software method was used to improve resolution between differing weight loss events. This method allows for the definition of a set of parameters that, when met, will switch the constant temperature scan to an isothermal hold at the current temperature when a significant weight loss event is detected. Once the weight loss slows, the temperature scan resumes. This technique is especially useful in analyzing crumb rubber, as the oil and polymer components tend to have similar weight loss onsets.

## Inorganic Analysis

Inorganic constituents were determined by Galbraith Laboratories, Inc. (Knoxville, TN), using inductively coupled plasma (ICP)–mass spectrometry (MS) or ICP–atomic emission spectrometry (AES). Briefly, duplicate samples of 150–300 mg of crumb rubber were analyzed for arsenic, lead, barium, manganese, nickel, cadmium, and tin by ICP–MS (Galbraith method ME-30) using a Sciex Elan 6000, 6100, or 9000 (PerkinElmer, Waltham, MA) and for aluminum, cobalt, chromium, copper, iron, potassium, magnesium, sodium, silicon, and zinc by ICP–AES (Galbraith method ME-70) using a PerkinElmer Optima 4300 (PerkinElmer, Waltham, MA).

## Headspace Gas Chromatography–Mass Spectrometry Analysis for Volatile and Semivolatile Organic Compounds

Crumb rubber was analyzed using a headspace gas chromatography (GC)–MS method to determine volatile (VOC) and semivolatile (SVOC) organic compounds. The method was based on EPA method 8620B, which is designed to analyze for volatile organic compounds with boiling points less than 200ºC in solid matrices by GC–MS. The system used was a CTC Analytics CombiPAL autosampler (Leap Technologies, Carrboro, NC), coupled to a 6890 GC and a 5973 MSD (Agilent Technologies, Santa Clara, CA). Duplicate crumb rubber samples (2 g) were weighed into 10-mL headspace vials and capped (Supelco, Bellefonte, PA). Vials were incubated at varying temperatures (ambient, 50°C or 100°C) for 40 minutes. One mL was sampled from the vial headspace and injected at 500 μL/second into the GC injector port at 240°C in splitless mode. An RTX-VMS column (60 m × 0.25 mm, 1.4-μm film thickness, Restek, Bellefonte, PA) was used with the following oven temperature program: 40°C held for 5 minutes, increased at 2°C per minute to 80°C, followed by increases at 4°C per minute to 245°C, and held for 15 minutes. The mass spectrometer conditions were ionization mode, electron ionization; auxiliary temperature, 240°C; ion source temperature, 250°C; quadrupole temperature, 150°C; and scan range, m/z 35 to 500. Total run time was ~81 minutes.

A single concentration of standards of potential crumb rubber constituents (~130), a subset of those given in Appendix A, except the alkanes mix (see below), was prepared in either 2-phenoxyethanol or methanol. The concentration of individual standards ranged from 0.1 to 160 μg/mL, to cover the expected range in crumb rubber, based on preliminary experiments. The compounds with low boiling points were prepared in the late-eluting 2-phenoxyethanol and compounds with higher boiling points were prepared in the early-eluting methanol to prevent interference of the solvent with the standard during analysis. Because the alkanes mix was procured in hexane, it was diluted with hexane. The standards were spiked (25 μL) into 10-mL headspace vials approximately half filled with 1-mm glass beads (Sigma-Aldrich, St. Louis, MO). Method blanks were prepared by using glass beads or glass beads spiked with 25 μL of the respective solvent used for the standards that were prepared for analysis.

Constituents in crumb rubber were identified using a combination of retention times of analytical standards and their mass spectra and library matches of mass spectra using the combined NIST 2014 and Wiley 11th Edition Mass Spectral Library (NIST/Wiley Library) (Wiley, Hoboken, NJ). For the alkanes larger than decane, the abundance of the higher mass fragments (>m/z 100) was too low to be detected in the samples (and sometimes in the standards with higher concentration), so the identity was based on the pattern of low mass fragments (serial losses of CH_2_) and retention time match with the standard. Although straight-chain alkane standards were used for identification, the identified peaks could be branched isomers of other alkanes. Because the profiles of the duplicate samples were nearly identical, peaks were identified using one replicate only.

Under the experimental conditions mentioned above, the level of each compound in the samples that matched with a standard was estimated using the response factor of a single concentration of standard. This estimate assumes the compounds volatilized similarly in the crumb rubber samples and standards spiked on glass beads. Meta- and para-xylene were not separated by this method and have nearly identical mass spectra. Therefore, the concentration for the peak was estimated using the m-xylene response factor given that commercial xylenes are predominantly m-xylene.

## Estimation of Solvent-Extractable Constituents Fraction

To determine the solvent-extractable fraction, 0.5-g portions of crumb rubber were extracted, in duplicate, by rotation overnight at ambient temperature at ~70 rpm with 10 mL of water, ethanol, ethyl acetate, hexane, methylene chloride, or carbon disulfide. Samples were centrifuged for 5 minutes at 3,000 rpm and the supernatant removed. The residual crumb rubber was dried at 60°C for 2 days and weighed to determine the percentage extracted.

## Gas Chromatography–Mass Spectrometry Analysis of Solvent-Extractable Constituents Fraction

All solvent extracts from above were analyzed by GC–MS using a 7890 GC coupled to a 5975 MSD (Agilent Technologies, Santa Clara, CA). One μL of extract was injected into the GC injector port at 300°C in splitless mode. A DB-5MS column (60 m × 0.25 mm, 0.25-μm film thickness, Agilent, Santa Clara, CA) was used with a helium carrier gas flow at 1 mL per minute. The initial oven temperature was 40°C, which was ramped to 330°C, at 5°C per minute and held for 5 minutes. The mass spectrometer conditions were ionization mode, electron ionization; auxiliary temperature, 300°C; ion source temperature, 250°C; quadrupole temperature, 200°C; and scan range, m/z 35 to 650. Total run time was ~68 minutes.

Chromatograms from methylene chloride extract were used to identify crumb rubber constituents. Standards for some potential crumb rubber constituents (listed in Appendix A) that are expected to elute after the solvent were prepared in methylene chloride (except the alkanes mix) or hexane (alkanes mix). All standards were prepared at a sufficiently high concentration (40 μg/mL) to be able to obtain mass spectra with sufficient fragments above the detection limit to allow for identification. Blanks containing either the solvent used for the extraction and the standards also were prepared for analysis.

To identify as many constituents as possible, the following criteria were used: (1) comparison with the retention time and spectra of analytical standards followed by comparison of mass spectra to the NIST/Wiley library (Wiley, Hoboken, NJ) (targeted analysis); (2) search for potential crumb rubber constituents (Appendix B) in the chromatogram using extracted ion chromatograms for the parent and significant unique fragment ions such as halides, followed by comparison of the mass spectrum to the NIST/Wiley library (suspect screening); and (3) comparison of mass spectra of unknown peaks with area percent greater than 0.1% in the total chromatogram with the NIST/Wiley library (non-targeted analysis).

## Liquid Chromatography–Mass Spectrometry Analysis of Solvent-Extractable Constituents

An ethanol extract (prepared as described above, except using 2 g crumb rubber) was analyzed by LC–MS using an Agilent 1100 Liquid Chromatograph (Agilent, Santa Clara, CA) coupled to an API 4000 QTrap MS (Sciex, Toronto, Canada) using electrospray ionization (ESI) and atmospheric pressure chemical ionization (APCI) sources in both positive and negative ion modes. The data system used was Analyst (1.6.1), ACD (Toronto, Canada) Spectrus (2017.1.2). The mass spectrometer was operated in enhanced MS mode with dynamic ion trap fill time, 1000 Da/sec ion trap readout rate, and scanning from m/z 50 to 450. A low wavelength UV (210 nm) chromatogram also was collected. Analyte separation was achieved on a Phenomenex (Torrance, CA) Kinetex Biphenyl column (150 × 3.0 mm, 2.6-μm particle size). Mobile phases, 0.1% formic acid in water (A), and 0.1% formic acid in acetonitrile (B), were used at a linear gradient of 10% B to 13.4% B over 3 minutes, followed by 100% B over 77 minutes with a flow rate of 300 μL/minute.

Standards of several of the largest constituents observed in the GC–MS analyses of VOCs, SVOCs, and solvent extracts were prepared in ethanol at 10 and 100 μg/mL. The standards and blank ethanol were analyzed using the same methods used for the samples.

To identify constituents in crumb rubber, the following approach was used: (1) combination of retention times of analytical standards and corresponding spectra (targeted analysis), (2) search for molecular weight of the constituents identified in the GC–MS analysis and in the Handbook for the Chemical Analysis of Plastic and Polymer Additives^14^ (suspect screening), and (3) comparison of the mass spectra of unknown peaks against the Massbank (h[underlined: ttp://www.massbank.jp]) library (non-targeted analysis).

## Size Fractionation of Crumb Rubber Lot and Gas Chromatography–Mass Spectrometry Profiling of Fractions

To generate different sized fractions for use in NTP research, samples of the crumb rubber lot were sieved using mesh sizes 14 (≥1.41 mm), 40 (0.420–1.41 mm), 80 (0.177–0.420 mm), and 400 (0.037–0.177 mm), and the weight % of each fraction was recorded (note: theoretical particle sizes are given in parentheses). Small aliquots from 14-, 40-, and 80-mesh sizes were removed for analysis, and the remaining material was combined to generate one fraction (14- to 80-mesh). The 400-mesh was saved separately. Duplicate samples from mesh fractions 14-, 40-, 80-,14- to 80-, and 400-mesh were analyzed, along with the original bulk material, by the headspace GC–MS method as described above using 100°C as the incubation temperature. Concentrations of selected VOCs and SVOCs were estimated as described above for the unsieved bulk material.

The spectral data from duplicate analyses were imported into XCMS software (https://xcmsonline.scripps.edu) for non-targeted analysis using multivariate statistics and settings used are given in Appendix D. The software was set to find features that differed between samples at the 95% confidence level and had at least a 3:1 signal-to-noise ratio to find the most significant differences. The data were presented as a cloud plot and principal component analysis (PCA) score plot using both spectral features and peaks.

Solo v8.5.1 software (Eigenvector Research, Manson, WA) was used to perform PCA analysis and hierarchical cluster analysis using Ward’s method using peaks in the profiles (instead of spectral features). This technique compares the overall profile of peaks rather than extracted ion chromatograms for every mass.

## Energy Dispersive X-Ray Spectroscopy of Crumb Rubber Fractions

The bulk material was size fractionated (mesh sizes 400, 80, 40, and 14) and the three larger particle size fractions (mesh sizes 80, 40, and 14) were combined, resulting in two fraction lots [Lot No. CRM12052016 (combined material) and Lot No. CRM09132016 (400-mesh^12^)]. EDS were done on both these lots using an Apollo X silicon drift detector (EDAX, Mahwah, NJ). Spectra of 10 particles from each lot were analyzed and the weight percent of the elements detected were estimated.

## Bioaccessibility In Vitro

To determine whether crumb rubber constituents are bioaccessible, crumb rubber was extracted with simulated biofluids to mimic dermal, inhalation, and oral (ingestion) routes of exposures. The simulated sweat, lung fluid, saliva, gastric fluid, and intestinal fluid, and their combination in ingestion pathway fluid, were prepared as described by Pavilonis et al. (2016)^15^; the composition of each fluid are given in Appendix E. Briefly, for simulated dermal exposure, 400-mg aliquots of crumb rubber were incubated in 20 mL of simulated sweat medium at 37ºC for approximately 1 hour. For simulated inhalation exposure, 200 mg of crumb rubber were incubated in 10 mL of simulated lung fluid for approximately 24 hours. For simulated ingestion exposure, 8 mL of simulated saliva were added to 2 g of crumb rubber and shaken for ~30 seconds. After adding 100 mL of simulated gastric fluid, the sample was incubated at 37°C for approximately 2 hours. Approximately 50 mL of the extract was pipetted into another bottle to serve as the gastric phase-only sample. To the remaining sample (containing the crumb rubber) 100 mL of simulated intestinal fluid was added (final pH 6.5) and incubated at 37ºC for approximately 2 hours. All extracts from the above-mentioned incubations were filtered through 0.45-μm syringe filters to remove any crumb rubber particles and analyzed as described below.

The headspace GC–MS analysis of samples was conducted as described previously using a 300 μL of each extract in duplicate in 10-mL vials containing ~2 g of glass beads. For the analysis by liquid injection GC–MS under the conditions described previously, 4 mL of each crumb rubber extract prepared as described above were rotated end over end with 4 mL of methylene chloride for approximately 1 hour. The samples were centrifuged for 5 minutes at 1,800 g, and the methylene chloride layers were transferred to autosampler vials for analysis. For the LC–MS analysis, the simulated biofluid extracts and blanks were analyzed as is. Method blanks were prepared similarly for all analysis methods except for the addition of crumb rubber. Instruments and the chromatographic methods used were the same as those described above except for the following: Both headspace and liquid injection GC–MS analyses were performed for constituents identified in crumb rubber above using selected ion monitoring (SIM) where one ion (generally the m/z of the molecular ion) was used as the quantitation ion and a second ion as a confirmation ion that must be present to confirm identity. To keep the mass spectrometer data acquisition cycle time short enough to generate a sufficient number of data points to improve sensitivity, the samples and blanks were injected three times with a different set of SIM ions monitored each time. The grouping of ions was based on mass and retention time. Compounds with similar masses or retention times were assigned into different groups to prevent any potential interferences from closely eluting compounds. The LC–MS analyses were performed using full scan (m/z 50 to 450), and extracted ion chromatograms for the [M+H]^+^ ion of each compound were generated. An estimated concentration of each compound found in the analyses was calculated using the response factor of the standard.

Stock standards of 32 selected compounds (based on the analytes found in crumb rubber and previous screening; see Results section) were prepared at 2 mg/mL in methylene chloride (except 2-methylnaphthalene and 1-methylnaphthalene, which were purchased as a 1-mg/mL and 2-mg/mL solution in methanol). The stock standards were combined into three intermediate standard mixes containing approximately 100 μg/mL of each compound in methylene chloride. For the headspace GC–MS analysis, 50 μL of each intermediate standard mix was diluted to 10 mL in ASTM Type 1 water to produce standards at 500 ng/mL. As with the samples, 300 μL of each standard mix was pipetted into 10-mL headspace vials containing ~2 g of glass beads. For the liquid injection GC–MS analysis, 50 μL of each intermediate standard mix was diluted to 10 mL in methylene chloride to produce standards at 500 ng/mL. For LC–MS analysis, stock standards were combined into three standard mixes containing approximately 20 μg/mL of each compound in ethanol. The standards were prepared at a higher concentration than the GC–MS due to the lower sensitivity of the full-scan analysis.