# Introduction

Synthetic turf fields are widely used in the United States, and their use is expanding. Although such fields historically have been installed in professional sports complexes, they are becoming increasingly popular in community recreational areas, including schools and public parks. These expanded applications include areas across the United States that are used by people of all ages, including young children. In a synthetic turf field, infill materials are spread between the “grass” fibers to provide cushioning and traction. Today, most commonly, the infill consists of granulated rubber pellets referred to as crumb rubber. Crumb rubber is manufactured by shredding used or recycled automobile tires. Recycled tires contain numerous, potentially carcinogenic and toxic substances, either as components of the original tire rubber or accumulated during normal use. While information is known about tire manufacturing, many variables are unknown, including persistence of byproducts, chemical changes during vulcanization, and adsorption of environmental chemicals, which might affect the chemical composition of the ultimate crumb rubber product. A recent literature review of crumb rubber chemical characterization studies outlines some chemicals of concern; using ADMET Predictor™, this study identified 197 predicted carcinogens, of which 52 have been previously classified as carcinogens by the U.S. Environmental Protection Agency (EPA) or European Chemicals Agency (ECHA).^1^ Other chemicals of concern as well as more information about crumb rubber manufacturing and synthetic turf construction and standards, are described in the 2016 EPA Federal Research Action Plan.^2^

Public concerns about potential health impacts associated with the use of synthetic turf fields have risen dramatically in recent years due to the chemical composition of crumb rubber and the opportunity for widespread, frequent, and long-term exposure, particularly for young athletes. Considering that information to evaluate whether there are adverse health effects from playing on synthetic turf fields is currently limited, several governmental organizations at the international, federal, and state level recently launched research efforts to better understand human exposure and human health hazards focusing on crumb rubber. Internationally, ECHA^3^ and the National Institute for Public Health and the Environment (RIVM)^4^ of the Netherlands have evaluated the health risks of playing sports on synthetic turf with crumb rubber. The Federal Research Action Plan,^5-7^ which involves several U.S. federal agencies, aims to determine and fill important knowledge gaps (FRAP 2016, Appendix B), characterize constituents of recycled tire crumb, and identify ways that people are exposed to tire crumb rubber through typical field use activities. The California Office of Environmental Health Hazard Assessment (OEHHA)^8^ is evaluating exposure scenarios, characterizing new and in-field crumb rubber, and developing biomonitoring protocols.

In 2015, OEHHA nominated synthetic turf/crumb rubber to the National Toxicology Program (NTP) for short-term in vivo and in vitro studies to generate information and improve understanding of potential health impacts of chemicals released from synthetic turf, with an emphasis on crumb rubber. The NTP research program^9^ developed in response to this request used in vitro and in vivo systems to address uncertainties about potential human exposure to hazardous components of crumb rubber. The NTP research approach included both in vivo and in vitro studies and considered the most likely routes of human contact with crumb rubber (e.g., ingestion, dermal contact, and inhalation). The study objective was to investigate which exposure conditions could have biological effects, with a focus on characterizing the bioaccessibility and systemic exposure of crumb rubber constituents.

The results of the NTP studies on crumb rubber are communicated in a series of Research Reports.^10-13^ The crumb rubber used in the NTP studies was provided by OEHHA specifically for research purposes, and consisted of fresh recycled tire crumb rubber obtained from manufacturing facilities. The physical and chemical characteristics of the material were evaluated using a variety of analytical methods.^10^ The characterization work provided an understanding of the material used in the NTP studies and helped interpret chemical analyses in the in vivo and in vitro studies. Characterization of the NTP material will allow interpretation of NTP study findings in relation to crumb rubber evaluated as part of the Federal Research Action Plan (FRAP) and OEHHA research efforts, including samples from new and weathered material, and samples from indoor and outdoor fields. For in vitro testing, multiple cell lines (representing skin, lung, and small intestine) were used to evaluate the extractability of crumb rubber and to look for evidence of biological activity of crumb rubber constituents via measurements of cytotoxicity.^11^ For in vivo studies, feasibility testing was conducted to determine what routes of exposure were possible.^12^ On the basis of this testing, 14-day in vivo studies were performed^13^ using oral exposure and exposure in bedding. Dermal studies were not conducted on the basis of feasibility work,^12^ and feasibility testing for particle and vapor inhalation studies is ongoing.

This report focuses on characterizing a crumb rubber lot for use in NTP research activities. A composite lot of crumb rubber was prepared from commercial material obtained from multiple sources via OEHHA (see Materials and Methods). The lot may or may not represent what is found from other sources or on synthetic turf fields of different ages. The lot was analyzed using a variety of techniques to generate information on its chemical and physical characteristics. The lot was sieved to generate different size fractions to be used in animal toxicology studies via different exposure scenarios.^12,13^ In vitro bioaccessibility studies were conducted to mimic various routes of exposure to investigate potential crumb rubber constituents bioaccessible under these conditions.