# Appendix E Bioaccessibility Studies

Table E-1 Composition of Media Used in Bioaccessibility Studies

Simulated Biofluid | Component | Concentration
Sweat | Sodium chloride | 340 mM
Sweat | Ammonium chloride | 330 mM
Sweat | Urea | 83 mM
Sweat | Lactic acid | 170 mM
Sweat | Acetic acid | 42 mM
Lung Fluid | Sodium chloride | 150 mM
Lung Fluid | Potassium chloride | 4 mM
Lung Fluid | Magnesium chloride | 10 mM
Lung Fluid | Sodium phosphate dibasic | 1 mM
Lung Fluid | Sodium sulfate | 5 mM
Lung Fluid | Calcium chloride | 25 mM
Lung Fluid | Sodium acetate | 7 mM
Lung Fluid | Sodium bicarbonate | 24 mM
Lung Fluid | Sodium citrate | 3 mM
Lung Fluid | Dipalmitoyl lecithin | 0.2%
Saliva^a^ | Sodium chloride | 7 mM
Saliva^a^ | Calcium chloride | 4 mM
Saliva^a^ | Potassium chloride | 5 mM
Saliva^a^ | Sodium phosphate dibasic | 4 mM
Saliva^a^ | Urea | 17 mM
Saliva^a^ | Mucin | 0.4%
Gastric Fluid^a^ | Sodium chloride | 30 mM
Gastric Fluid^a^ | Pepsin | 200 mM
Gastric Fluid^a^ | Hydrochloric acid | 84 mM
Intestinal Fluid^a^ | Sodium bicarbonate | 200 mM

^a^ Gastric only ingestion phase consisted of extraction with simulated saliva followed by simulated gastric fluid. Total ingestion consisted of simulated saliva followed by simulated gastric fluid and then simulated intestinal fluid.