# Appendix D Settings Used in XCMS Software

The XCMS software can be found online here: https://xcmsonline.scripps.edu.