# Appendix C Additional Constituents of Crumb Rubber Identified by Various Techniques

Table C-1 Constituents of Crumb Rubber in Methylene Chloride Extract Identified by GC–MS with Low Confidence^a^

Name | CAS | ID by Match with Standard^a^ | ID by Match with Reference^b^
Acenaphthylene | 208-96-8 | Yes | Yes
Acetophenone | 98-86-2 | No | Yes
Alpha Pinene | 80-56-8 | No | Yes
Aniline | 62-53-3 | No | Yes
Anthracene | 120-12-7 | Yes | Yes
Anthracene, 2-methyl- | 613-12-7 | No | Yes
Anthracene, 9-methyl- | 779-02-2 | No | Yes
Benz(a)anthracene | 56-55-3 | Yes | Yes
Benzenesulfonanilide | 1678-25-7 | No | Yes
Benzo(a)fluoranthene | 203-33-8 | No | Yes
Benzo(a)pyrene | 50-32-8 | Yes | Yes
Benzo(b)fluorene | 243-17-4 | No | Yes
Benzo(ghi)fluoranthene | 203-12-3 | No | Yes
Benzothiazole, 2-(methylthio)- | 615-22-5 | No | Yes
N,N'-Bis(2'-dimethylphosphinothioylethyl)-N,N'-diethylpropylenediamine | Unknown | No | Yes
Bisphenol P | 2167-51-3 | No | Yes
p-tert-butyl Phenol | 98-54-4 | No | Yes
3-Carene | 13466-78-9 | No | Yes
Chrysene | 218-01-9 | Yes | Yes
Cyclohexane, 1,1,3-trimethyl- | 3073-66-3 | No | Yes
Cyclohexanone | 108-94-1 | No | Yes
m-Cymene | 535-77-3 | No | Yes
o-Cymene | 527-84-4 | No | Yes
p-Cymene | 99-87-6 | No | Yes
2,4'-Diaminotriphenylmethane | Unknown | No | Yes
Dicyclohexylamine | 101-83-7 | No | Yes
2,3-Dihydro-1,1,3-trimethyl-3-phenyl-1H-indene | 3910-35-8 | No | Yes
9,10-Dimethylanthracene | 781-43-1 | No | Yes
2,6-Dimethylnaphthalene | 581-42-0 | No | Yes
2,7-Dimethylphenanthrene | 1576-69-8 | No | Yes
2,6-Di(t-butyl)-4-hydroxy-4-methyl-2,5-cyclohexadien-1-one (BHT-OH) | 10396-80-2 | No | Yes
Ethylbenzene | 100-41-4 | No | Yes
2-Ethyl Hexanoic Acid | 149-57-5 | No | Yes
Fluorene | 86-73-7 | Yes | Yes
Hexadecanoic Acid, Methyl Ester | 112-39-0 | No | Yes
Hexatriacontane | 630-06-8 | No | Yes
1-Iodo-2-methylundecane | 73105-67-6 | No | Yes
Limonene | 5989-27-5 | No | Yes
2-Mercaptobenzothiazole | 149-30-4 | No | Yes
Methylcyclohexane | 108-87-2 | No | Yes
Methyl Elaidate | 1937-62-8 | No | Yes
2-α-Methyl-17-β-hopane | Unknown | No | Yes
2-Methylphenanthrene | 2531-84-2 | No | Yes
3-Methylphenanthrene | 832-71-3 | No | Yes
Neodecanoic Acid | 26896-20-8 | No | Yes
30-Norhopane | 36728-72-0 | No | Yes
Perylene | 198-55-0 | No | Yes
Phenol | 108-95-2 | No | Yes
1-Phenyl-1-butene | 1005-64-7 | No | Yes
1-Propynylbenzene | 673-32-5 | No | Yes
2-Phenyl Benzothiazole | 883-93-2 | No | Yes
Pyrene, 1-methyl- | 2381-21-7 | No | Yes
Stigmasta-5,24(28)-dien-3-ol | 17605-67-3 | No | Yes
Styrene | 100-42-5 | No | Yes
Tetratriacontane | 14167-59-0 | No | Yes
Trichloroethylene | 79-01-6 | No | Yes
2,4,4-Trimethylpentene | 107-40-4 | No | Yes
1,2,4-Trimethylbenzene | 95-63-6 | No | Yes
1,3,5-Trimethylbenzene | 108-67-8 | No | Yes
m-Xylene | 108-38-3 | No | Yes
o-Xylene | 95-47-6 | No | Yes
p-Xylene | 106-42-3 | No | Yes

^a^ Identification of constituents was done with retention time and a partial mass spectral match with a standard, a 30–84% match with a library reference spectrum, or both.

^b^ Indicates a 30–84% match with a library reference spectrum.

Table C-2 Constituents Not Found in Methylene Chloride Extracts of Crumb Rubber (No Peak for the Molecular Ion or with a Library Match Exceeding 30%)

Name | CAS
Acetic Acid | 64-19-7
trans-Anethole | 50770-19-9
Anthanthrene | 191-26-4
Azobenzene | 103-33-3
Benzamide, N-N-diethyl-3-methyl-” (DEET) | 134-62-3
Benzenamine, 4-octyl-N-(4-octylphenyl)- | 101-67-7
Benzene | 71-43-2
Benzene, 1-ethyl-2-methyl- (2-ET) | 611-14-3
Benzenemethanol, ar-ethenyl- | 53957-34-9
Benzidine | 92-87-5
Benzo(b)fluoranthene | 205-99-2
Benzo(g,h,i)perylene | 191-24-2
Benzo[k]fluoranthene | 207-08-9
Benzoic Acid | 65-85-0
Benzothiazole, 2-(morpholinothio)- | 102-77-2
1H-Benzotriazol-5-amine, 1-methyl- | 27799-83-3
Benzyl Alcohol | 100-51-6
Biphenyl | 92-52-4
Bis(2-chloroethoxy)methane | 111-91-1
Bis(2-chloroethyl)ether | 111-44-4
Bromodichloromethane | 75-27-4
Bromoform | 75-25-2
4-Bromophenyl Phenyl Ether | 101-55-3
Butane, 2-iodo-2-methyl- | 594-38-7
1-Butanol, 4-methoxy- | 111-32-0
2-Butanone | 78-93-3
2-Butoxyethanol | 111-76-2
2-(2-Butoxyethoxy)ethanol | 112-34-5
2-(2-Butoxyethoxy)ethyl acetate | 124-17-4
sec-Butylbenzene | 135-98-8
Butyl Butanoate | 109-21-7
Butyl Benzyl Phthalate | 85-68-7
n-tert-Butylbenzothiazolesulfenamide | 95-31-8
Carbon Tetrachloride | 56-23-5
4-Chloroaniline | 106-47-8
Chlorobenzene | 108-90-7
Chloroethane | 75-00-3
2-Chloroethyl Vinyl Ether | 110-75-8
1-Chloro-2-ethenyl-1-methylcyclopropane | 62337-93-3
4-Chloro-3-methylphenol | 59-50-7
2-Chloronaphthalene | 91-58-7
2-Chlorophenol | 95-57-8
4-Chlorophenyl Phenyl Ether | 7005-72-3
4-Chlorotoluene | 106-43-4
Cinnamaldehyde | 14371-10-9
Cycloheptane | 291-64-5
Cyclohexane | 110-82-7
Cyclohexane, 1,3-dimethyl-, cis- | 638-04-0
Cyclohexane, 1,4-dimethyl- | 589-90-2
Cyclohexane, ethyl- | 1678-91-7
Cyclohexanol | 108-93-0
Cyclohexyl Isothiocyanate | 1122-82-3
Decamethyl Cyclopentasiloxane | 541-02-6
Decanal | 112-31-2
Decane | 124-18-5
Decane, 5-methyl- | 13151-35-4
Decane, 6-ethyl-2-methyl- | 62108-21-8
Decane, 2,3,8-trimethyl- | 62238-14-6
Decane, 2,5,6-trimethyl- | 62108-23-0
Dehydroabietic Acid | 1740-19-8
Dibenz(a,h)anthracene | 53-70-3
Dibenzofuran | 132-64-9
3-Dibenzofuranamine | 4106-66-5
4-Dibenzofuranamine | 50548-43-1
2-Dibenzofuranamine | 3693-22-9
Dibenzothiophene | 132-65-0
Dibromochloromethane | 124-48-1
Di-n-butyl Phthalate | 84-74-2
1,2-Dichlorobenzene | 95-50-1
1,3-Dichlorobenzene | 541-73-1
1,4-Dichlorobenzene | 106-46-7
3,3'-Dichlorobenzidine | 91-94-1
1,1-Dichloroethane | 75-34-3
1,2-Dichloroethane | 107-06-2
trans-1,2-Dichloroethene | 951-86-0
2,4-Dichlorophenol | 120-83-2
Diethyl Phthalate | 84-66-2
Dimethyl Adipate | 627-93-0
Dimethyl Pentanedioate | 1119-40-0
2,4-Dimethylphenol | 105-67-9
Dimethyl Phthalate | 131-11-3
Dimethyl Succinate | 106-65-0
4,6-Dinitro-2-methylphenol | 534-52-1
2,4-Dinitrophenol | 51-28-5
2,4-Dinitrotoluene | 121-14-2
2,6-Dinitrotoluene | 606-20-2
Di-n-octyl Phthalate | 117-84-0
1,3-Divinylbenzene | 108-57-6
Dodecanal | 112-54-9
Dodecane | 112-40-3
Dodecane, 2,6,11-trimethyl- | 31295-56-4
Dodecane, 2,7,10-trimethyl- | 74645-98-0
2-Dodecen-1-yl Succinic Anhydride | 19780-11-1
Ethyl Benzoate | 93-89-0
Ethylbenzaldehyde | 4748-78-1
2-Ethyl-1-hexanol | 104-76-7
4-Ethyltoluene (4-ET) | 622-96-8
2(3H)-Furanone, dihydro-4-hydroxy- | 5469-16-9
Heptane | 142-82-5
Heptane, 2,2-dimethyl- | 1071-26-7
Heptane, 2,3,4-trimethyl- | 52896-95-4
Heptane, 2,4-dimethyl- | 2213-23-2
Heptane, 2,5-dimethyl- | 2216-30-0
Heptane, 2,6-dimethyl- | 1072-05-5
Heptane, 2-methyl- | 592-27-8
Heptane, 3-methyl- | 589-81-1
Heptane, 4-(1-methylethyl)- | 52896-87-4
1-Heptene | 592-76-7
Hexachlorobenzene | 118-74-1
Hexachlorobutadiene | 87-68-3
Hexachlorocyclopentadiene | 77-47-4
Hexachloroethane | 67-72-1
Hexadecane | 544-76-3
Hexadecanoic Acid, Butyl Ester | 111-06-8
Hexanal | 66-25-1
Hexane, 2,2,4-trimethyl- | 16747-26-5
Hexane, 2,2,5-trimethyl- | 111-84-2
Hexane, 3,3-dimethyl- | 563-16-6
Hexane, 3-methyl- | 589-34-4
2-Hexanone (MBK) | 591-78-6
1-Hexene, 4,5-dimethyl- | 16106-59-5
2-Hexen-1-ol, (Z)- | 928-94-9
2-Hexen-1-ol, (Z)- | 928-94-9
5-Hexen-2-ol, (+/-)- | 54774-27-5
Hydroxylamine, O-decyl- | 29812-79-1
2-Hydroxybenzothiazole | 934-34-9
3H-Indazol-3-one, 1,2-dihydro-2-methyl- | 1848-40-4
4-Isopropylphenol | 99-89-8
Indeno(1,2,3-cd)pyrene | 193-39-5
Isobutyl Alcohol | 78-83-1
Isophorone | 78-59-1
Isopropylbenzene | 98-82-8
Menthol | 1490-04-6
Methanimidamide, N,N-dimethyl-N'-phenyl- | 1783-25-1
1-Methoxy-2-propanol | 107-98-2
6-Methylbenzo[b]thiophene | 16587-47-6
2-Methylbenzothiazole | 120-75-2
4-Methyl-4-heptanol | 598-01-6
2-Methylhexane | 591-76-4
2-Methylphenol (o-Cresol) | 95-48-7
4-Methylphenol (p-Cresol) | 106-44-5
1-Methyl-2-pyrrolidinone | 872-50-4
Methyl α-D-xylofuranoside | 1824-96-0
Methyl Salicylate | 119-36-8
2-Nitroaniline | 88-74-4
3-Nitroaniline | 99-09-2
4-Nitroaniline | 100-01-6
Nitrobenzene | 98-95-3
Nitromethane | 75-52-5
2-Nitrophenol | 88-75-5
4-Nitrophenol | 100-02-7
N-Nitrosodimethylamine | 62-75-9
N-Nitroso-di-n-propylamine | 621-64-7
N-Nitrosodiphenylamine | 86-30-6
Nonanal | 124-19-6
Nonanamide | 1120-07-6
Nonane | 111-84-2
Nonane, 3-methyl-5-propyl- | 31081-18-2
Octadecanoic Acid/Stearic Acid | 57-11-4
Octane | 111-65-9
Octane, 2-methyl- | 3221-61-2
Octane, 3-methyl- | 2216-33-3
2-Octen-1-ol | 18409-17-1
Oleic Acid | 112-80-1
2,2'-Oxybis(1-chloropropane) | 108-60-1
Pentachlorophenol (PCP) | 87-86-5
Pentadecane | 629-62-9
2,2,4,6,6-Pentamethylheptane | 13475-82-6
Pentanamide, 4-methyl- | 1119-29-5
Pentane, 2,2,3,4-tetramethyl- | 1186-53-4
Pentane, 3,3-dimethyl- | 562-49-2
Pentenylbenzene | 826-18-6
Phenol, 2,2'-methylenebis(6-(1,1-dimethylethyl)-4-ethyl- | 88-24-4
1,2-Propanediol | 57-55-6
2-Propanol | 67-63-0
n-Propylbenzene | 103-65-1
2-Propyl-methyl penatanoic Acid | 31113-56-1
1,1,2,2-Tetrachloroethane
Tetrachloroethene | 127-18-4
Tetradecane | 629-59-4
Tetradecane, 1-chloro- | 2425-54-9
Tetradecanoic Acid | 544-63-8
Tetrahydrofuran | 109-99-9
1,2,4-Trichlorobenzene | 120-82-1
2,4,5-Trichlorophenol | 95-95-4
2,4,6-Trichlorophenol | 88-06-2
Tridecane | 629-50-5
2,3,6-Trimethylanisole | 21573-36-4
2,2,7-Trimethyl-3-octyne | 55402-13-6
TXIB | 6846-50-0
Undecane | 1120-21-4
Undecane, 2,6-dimethyl- | 17301-23-4
Undecane, 3-methyl- | 1002-43-3
Undecane, 4,6-dimethyl- | 17312-82-2
Undecane, 4-methyl- | 2980-69-0
Undecane, 5,6-dimethyl- | 17615-91-7
Vinyl Acetate | 108-05-4

^a^ No peak for the molecular ion or with a library match exceeding 30%.