# Appendix B Potential Crumb Rubber Constituents Identified in the Literature and Initial Screening Analyses

Table B-1 Potential Constituents in Crumb Rubber Based on Literature^a^ and Initial Screening

Name | CASRN | Molecular Wt
Acenaphthene | 83-32-9 | 154.21
Acenaphthylene | 208-96-8 | 152.20
Acetaldehyde | 75-07-0 | 44.05
Acetic Acid | 64-19-7 | 60.05
Acetone | 67-64-1 | 58.08
Acetonitrile | 75-05-8 | 41.05
Acetophenone | 98-86-2 | 120.15
Allyl Chloride | 107-05-1 | 76.52
Alpha Pinene | 80-56-8 | 136.24
trans-Anethole | 50770-19-9 | 148.21
Aniline | 62-53-3 | 93.13
Anthanthrene | 191-26-4 | 276.34
Anthracene | 120-12-7 | 178.23
Anthracene, 2-methyl- | 613-12-7 | 192.26
Anthracene, 9-methyl- | 779-02-2 | 192.26
Azobenzene | 103-33-3 | 182.23
Benz(a)anthracene | 56-55-3 | 228.29
Benzamide, N-N-diethyl-3-methyl- (DEET) | 134-62-3 | 191.27
Benzenamine, 4-octyl-N-(4-octylphenyl)- | 101-67-7 | 393.66
Benzene | 71-43-2 | 78.14
1,4-Benzenediamine, N-(1,3-dimethylbutyl)-N'-phenyl- (6PPD) | 793-24-8 | 268.40
1,4-Benzenediamine, N-(1-methylethyl)-N'-phenyl- (IPPD) | 101-72-4 | 226.32
Benzene, 1-ethyl-2-methyl-(2-ET) | 611-14-3 | 120.20
Benzenemethanol, ar-ethenyl- | 53957-34-9 | 136.19
Benzenesulfonanilide | 1678-25-7 | 233.29
Benzidine | 92-87-5 | 184.24
Benzo(a)fluoranthene | 203-33-8 | 252.32
Benzo(a)pyrene | 50-32-8 | 252.32
Benzo(b)fluoranthene | 205-99-2 | 252.31
Benzo(b)fluorene | 243-17-4 | 216.28
Benzo(e)pyrene | 192-97-2 | 252.32
Benzo(g,h,i)perylene | 191-24-2 | 276.33
Benzo(ghi)fluoranthene | 203-12-3 | 226.28
Benzo[k]fluoranthene | 207-08-9 | 252.32
Benzoic Acid | 65-85-0 | 122.12
Benzothiazole | 95-16-9 | 135.18
Benzothiazole, 2-(methylthio)- | 615-22-5 | 181.27
Benzothiazole, 2-(morpholinothio)- | 102-77-2 | 252.35
1H-Benzotriazol-5-amine, 1-methyl- | 27799-83-3 | 148.17
Benzyl Alcohol | 100-51-6 | 108.14
Biphenyl | 92-52-4 | 154.21
Bis(2-chloroethoxy)methane | 111-91-1 | 173.04
Bis(2-chloroethyl)ether | 111-44-4 | 143.01
N,N'-Bis(2'-dimethylphosphinothioylethyl)-N,N'-Diethylpropylenediamine | Unknown | Unknown
Bis(2-ethylhexyl) Phthalate | 117-81-7 | 390.56
Bisphenol P | 2167-51-3 | 346.47
Bromodichloromethane | 75-27-4 | 163.82
Bromoform | 75-25-2 | 252.73
Bromomethane | 74-83-9 | 94.94
4-Bromophenyl Phenyl Ether | 101-55-3 | 249.11
1,3-Butadiene, 2-methyl- | 78-79-5 | 68.12
Butane | 106-97-8 | 58.12
Butane, 2-iodo-2-methyl- | 594-38-7 | 198.05
Butane, 2-methyl- | 78-78-4 | 72.15
1-Butanol, 4-methoxy- | 111-32-0 | 104.15
2-Butanone | 78-93-3 | 72.11
2-Butene, (E)- | 624-64-6 | 56.11
2-Butoxyethanol | 111-76-2 | 118.18
2-(2-Butoxyethoxy)ethanol | 112-34-5 | 162.23
2-(2-Butoxyethoxy)ethyl acetate | 124-17-4 | 204.27
Butylated Hydroxyanisole | 25013-16-5 | 180.25
Butylated Hydroxytoluene | 128-37-0 | 220.36
sec-Butylbenzene | 135-98-8 | 134.22
Butyl Butanoate | 109-21-7 | 144.21
n-tert-Butylbenzothiazolesulfenamide | 95-31-8 | 238.37
Butyl Benzyl Phthalate | 85-68-7 | 312.36
p-tert-Butyl Phenol | 98-54-4 | 150.22
2-Butyltetrathydrothiopene | Unknown | Unknown
Butyraldehyde | 123-72-8 | 72.11
Carbazole | 86-74-8 | 167.21
Carbon Disulfide | 75-15-0 | 76.13
Carbon Tetrachloride | 56-23-5 | 153.81
3-Carene | 13466-78-9 | 136.24
4-Chloroaniline | 106-47-8 | 127.57
Chlorobenzene | 108-90-7 | 112.56
Chloroethane | 75-00-3 | 64.51
1-Chloro-2-ethenyl-1-methylcyclopropane | 62337-93-3 | 116.59
2-Chloroethyl Vinyl Ether | 110-75-8 | 106.55
Chloroform | 67-66-3 | 119.37
Chloromethane | 74-87-3 | 50.49
4-Chloro-3-methylphenol | 59-50-7 | 142.58
2-Chloronaphthalene | 91-58-7 | 162.62
2-Chlorophenol | 95-57-8 | 128.56
4-Chlorophenyl Phenyl Ether | 7005-72-3 | 204.65
4-Chlorotoluene | 106-43-4 | 126.58
Chrysene | 218-01-9 | 228.29
Cinnamaldehyde | 14371-10-9 | 132.16
Cycloheptane | 291-64-5 | 98.19
Cyclohexane | 110-82-7 | 84.16
Cyclohexane, 1,3-dimethyl-, cis- | 638-04-0 | 112.22
Cyclohexane, 1,4-dimethyl- | 589-90-2 | 112.22
Cyclohexane, ethyl- | 1678-91-7 | 112.22
Cyclohexanethiol | 1569-69-3 | 116.22
Cyclohexane, 1,1,3-trimethyl- | 3073-66-3 | 126.24
Cyclohexanol | 108-93-0 | 100.16
Cyclohexanone | 108-94-1 | 98.15
Cyclohexyl isothiocyanate | 1122-82-3 | 141.23
Cyclopentane | 287-92-3 | 70.14
Cyclopentanone, 2-methyl- | 1120-72-5 | 98.15
Cyclopropyl Methyl Ketone | 765-43-5 | 84.12
m-Cymene | 535-77-3 | 134.22
o-Cymene | 527-84-4 | 134.22
p-Cymene | 99-87-6 | 134.22
Decamethyl Cyclopentasiloxane | 541-02-6 | 370.77
Decanal | 112-31-2 | 156.27
Decane | 124-18-5 | 142.29
Decane, 2,3,8-trimethyl- | 62238-14-6 | 184.37
Decane, 2,5,6-trimethyl- | 62108-23-0 | 184.36
Decane, 5-methyl- | 13151-35-4 | 156.31
Decane, 6-ethyl-2-methyl- | 62108-21-8 | 184.37
Dehydroabietic Acid | 1740-19-8 | 300.44
2,4'-Diaminotriphenylmethane | Unknown | 274.36
Dibenz(a,h)anthracene | 53-70-3 | 278.35
Dibenzofuran | 132-64-9 | 168.19
2-Dibenzofuranamine | 3693-22-9 | 183.21
3-Dibenzofuranamine | 4106-66-5 | 183.21
4-Dibenzofuranamine | 50548-43-1 | 183.21
Dibenzothiophene | 132-65-0 | 184.26
Dibromochloromethane | 124-48-1 | 208.28
Di-n-butyl Phthalate | 84-74-2 | 278.34
Di-n-octyl Phthalate | 117-84-0 | 390.56
2,6-Di(t-butyl)-4-hydroxy-4-methyl-2,5-cyclohexadien-1-one (BHT-OH) | 10396-80-2 | 236.36
3,5-Di-tert-butyl-4-hydroxybenzaldehyde | 1620-98-0 | 234.34
1,2-Dichlorobenzene | 95-50-1 | 147.00
1,3-Dichlorobenzene | 541-73-1 | 147.00
1,4-Dichlorobenzene | 106-46-7 | 147.00
3,3'-Dichlorobenzidine | 91-94-1 | 253.13
Dichlorodifluoromethane | 75-71-8 | 120.91
1,1-Dichloroethane | 75-34-3 | 98.95
1,2-Dichloroethane | 107-06-2 | 98.95
1,1-Dichloroethene | 75-35-4 | 96.94
2,4-Dichlorophenol | 120-83-2 | 163.00
1,2-Dichloropropane | 78-87-5 | 112.98
trans-1,3-Dichloropropene | 542-75-6 | 110.97
Dicyclohexylamine | 101-83-7 | 181.32
Diethyl Phthalate | 84-66-2 | 222.24
2,3-Dihydro-1,1,3-trimethyl-3-phenyl-1H-indene | 3910-35-8 | 236.36
1,2-Dihydro-2,2,4-trimethylquinoline | 147-47-7 | 173.26
Dimethyl Adipate | 627-93-0 | 174.20
9,10-Dimethylanthracene | 781-43-1 | 206.28
2,6-Dimethylnaphthalene | 581-42-0 | 156.23
Dimethyl Pentanedioate | 1119-40-0 | 160.17
2,7-Dimethylphenanthrene | 1576-69-8 | 206.29
2,4-Dimethylphenol | 105-67-9 | 122.16
Dimethyl Phthalate | 131-11-3 | 194.18
Dimethyl Succinate | 106-65-0 | 146.14
4,6-Dinitro-2-methylphenol | 534-52-1 | 198.13
2,4-Dinitrophenol | 51-28-5 | 184.11
2,4-Dinitrotoluene | 121-14-2 | 182.13
2,6-Dinitrotoluene | 606-20-2 | 182.13
1,3-Divinylbenzene | 108-57-6 | 130.19
Docosane | 629-97-0 | 310.61
Dodecanal | 112-54-9 | 184.32
Dodecane | 112-40-3 | 170.34
Dodecane, 2,6,11-trimethyl- | 31295-56-4 | 212.42
Dodecane, 2,7,10-trimethyl- | 74645-98-0 | 212.42
2-Dodecen-1-yl Succinic Anhydride | 19780-11-1 | 266.38
Dotriacontane | 544-85-4 | 450.88
Ethanol | 64-17-5 | 46.07
Ethyl Acetate | 141-78-6 | 88.11
Ethylbenzaldehyde | 4748-78-1 | 134.18
Ethylbenzene | 100-41-4 | 106.17
Ethyl Benzoate | 93-89-0 | 150.18
2-Ethyl Hexanoic Acid | 149-57-5 | 144.21
2-Ethyl-1-hexanol | 104-76-7 | 130.23
2-Ethyltetrahydrothiopene | Unknown | Unknown
4-Ethyltoluene | 622-96-8 | 120.19
Fluoranthene | 206-44-0 | 202.26
Fluorene | 86-73-7 | 166.22
Formaldehyde | 50-00-0 | 30.03
Freon 11 | 75-69-4 | 137.36
Freon 113 | 76-13-1 | 187.37
2(3H)-Furanone, dihydro-4-hydroxy- | 5469-16-9 | 102.09
Heneicosane | 629-94-7 | 296.58
Hentriacontane | 630-04-6 | 436.85
Heptacosane | 593-49-7 | 380.74
Heptadecane | 629-78-7 | 240.47
Heptane | 142-82-5 | 100.21
Heptane, 2,2-dimethyl- | 1071-26-7 | 128.26
Heptane, 2,3,4-trimethyl- | 52896-95-4 | 142.29
Heptane, 2,4-dimethyl- | 2213-23-2 | 128.26
Heptane, 2,5-dimethyl- | 2216-30-0 | 128.26
Heptane, 2,6-dimethyl- | 1072-05-5 | 128.26
Heptane, 2-methyl- | 592-27-8 | 114.23
Heptane, 3-methyl-e | 589-81-1 | 114.23
Heptane, 4-(1-methylethyl)- | 52896-87-4 | 142.29
1-Heptene | 592-76-7 | 98.19
2-Hexanone (MBK) | 591-78-6 | 100.16
Hexachlorobenzene | 118-74-1 | 284.78
Hexachlorobutadiene | 87-68-3 | 260.76
Hexachlorocyclopentadiene | 77-47-4 | 272.77
Hexachloroethane | 67-72-1 | 236.74
Hexacosane | 630-01-3 | 366.71
Hexadecane | 544-76-3 | 226.45
Hexadecanoic Acid, Butyl Ester | 111-06-8 | 312.53
Hexadecanoic Acid, Methyl Ester | 112-39-0 | 270.46
Hexanal | 66-25-1 | 100.16
Hexane | 110-54-3 | 86.18
Hexane, 2,2,4-trimethyl- | 16747-26-5 | 128.26
Hexane, 2,2,5-trimethyl- | 3522-94-9 | 128.26
Hexane, 3,3-dimethyl- | 563-16-6 | 114.23
Hexane, 3-methyl- | 589-34-4 | 100.21
Hexatriacontane | 630-06-8 | 506.98
1-Hexene, 4,5-dimethyl- | 16106-59-5 | 112.22
1-Hexene, 3,5,5-trimethyl- | 4316-65-8 | 126.24
2-Hexen-1-ol, (Z)- | 928-94-9 | 100.16
5-Hexen-2-ol, (.+/-.)- | 54774-27-5 | 100.16
3-[(E)-2-(4-Hexoxyphenyl)ethenyl]phenol | Unknown | 294.00
2-Hydroxybenzothiazole | 934-34-9 | 151.19
Hydroxylamine, O-decyl- | 29812-79-1 | 173.30
Icosane | 112-95-8 | 282.55
3H-Indazol-3-one, 1,2-dihydro-2-methyl- | 1848-40-4 | 148.17
Indeno(1,2,3-cd)pyrene | 193-39-5 | 276.33
1-Iodo-2-methylundecane | 73105-67-6 | 296.24
Isobutene | 115-11-7 | 56.11
Isobutyl Alcohol | 78-83-1 | 74.12
Isophorone | 78-59-1 | 138.21
Isopropylbenzene | 98-82-8 | 120.20
4-Isopropylphenol | 99-89-8 | 136.19
Isopropyltoluene (Cymenes) | 25155-15-1 | 134.22
Limonene | 5989-27-5 | 136.24
Menthol | 1490-04-6 | 156.27
2-Mercaptobenzothiazole | 149-30-4 | 167.24
Methanimidamide, N,N-dimethyl-N'-phenyl- | 1783-25-1 | 148.21
1-Methoxy-2-propanol | 107-98-2 | 90.12
Methyl α-D-xylofuranoside | 1824-96-0 | 164.16
6-Methylbenzo[b]thiophene | 16587-47-6 | 148.22
2-Methylbenzothiazole | 120-75-2 | 149.21
Methylcyclohexane | 108-87-2 | 98.19
Methyl Elaidate | 1937-62-8 | 296.50
Methylene Chloride | 75-09-2 | 84.93
4-Methyl-4-heptanol | 598-01-6 | 130.23
2-Methylhexane | 591-76-4 | 100.21
2.α.-Methyl-17.β.-hopane | Unknown | Unknown
1-Methylnaphthalene | 90-12-0 | 142.20
2-Methylnaphthalene | 91-57-6 | 142.20
4-Methyl-2-Pentanone (MIBK) | 108-10-1 | 100.16
2-Methylphenanthrene | 2531-84-2 | 192.26
3-Methylphenanthrene | 832-71-3 | 192.26
2-Methylphenol (o-Cresol) | 95-48-7 | 108.14
4-Methylphenol (p-Cresol) | 106-44-5 | 108.14
1-Methyl-2-pyrrolidinone | 872-50-4 | 99.13
Methyl Salicylate | 119-36-8 | 152.15
Methyl Stearate | 112-61-8 | 298.50
Naphthalene | 91-20-3 | 128.17
Neodecanoic Acid | 26896-20-8 | 172.27
2-Nitroaniline | 88-74-4 | 138.12
3-Nitroaniline | 99-09-2 | 138.12
4-Nitroaniline | 100-01-6 | 138.12
Nitrobenzene | 98-95-3 | 123.11
Nitromethane | 75-52-5 | 61.04
2-Nitrophenol | 88-75-5 | 139.11
4-Nitrophenol | 100-02-7 | 139.11
N-Nitrosodimethylamine | 62-75-9 | 74.08
N-Nitroso-di-n-propylamine | 621-64-7 | 130.19
N-Nitrosodiphenylamine | 86-30-6 | 198.22
Nonacosane | 630-03-5 | 408.80
Nonadecane | 629-92-5 | 268.53
Nonanal | 124-19-6 | 142.24
Nonanamide | 1120-07-6 | 157.26
Nonane | 111-84-2 | 128.26
Nonane, 3-methyl-5-propyl- | 31081-18-2 | 184.37
30-Norhopane | 36728-72-0 | 398.72
Octacosane | 630-02-4 | 394.77
Octadecane | 593-45-3 | 254.50
Octadecanoic Acid/Stearic Acid | 57-11-4 | 284.48
Octane | 111-65-9 | 114.23
Octane, 2-methyl- | 3221-61-2 | 128.26
Octane, 3-methyl- | 2216-33-3 | 128.26
2-Octen-1-ol (https://pubchem.ncbi.nlm.nih.gov/substance/319136983#section=Source-Category) | 18409-17-1 | 128.22
4-tert-Octylphenol | 140-66-9 | 206.33
Oleic Acid | 112-80-1 | 282.46
2,2'-Oxybis(1-chloropropane) | 108-60-1 | 171.06
Pentachlorophenol (PCP) | 87-86-5 | 266.32
Pentacosane | 629-99-2 | 352.69
Pentadecane | 629-62-9 | 212.42
1,3-Pentadiene | 504-60-9 | 68.12
1,4-Pentadiene | 591-93-5 | 68.12
2,2,4,6,6-Pentamethylheptane | 13475-82-6 | 170.34
Pentanamide, 4-methyl- | 1119-29-5 | 115.18
Pentane | 109-66-0 | 72.15
Pentane, 2,2,3,4-tetramethyl- | 1186-53-4 | 128.26
Pentane, 2-methyl- | 107-83-5 | 86.18
Pentane, 3,3-dimethyl- | 562-49-2 | 100.21
Pentatriacontane | 630-07-9 | 492.96
Pentenylbenzene | 1075-74-7 | 146.23
Perylene | 198-55-0 | 252.32
Phenanthrene | 65996-93-2 | 178.23
Phenol | 108-95-2 | 94.11
Phenol, 2,2'-methylenebis(6-(1,1-dimethylethyl)-4-ethyl- | 88-24-4 | 368.55
Phthalimide | 85-41-6 | 147.13
2-Phenyl Benzothiazole | 883-93-2 | 211.28
1-Phenyl-1-butene | 1005-64-7 | 132.21
1,2-Propanediol | 57-55-6 | 76.10
Propane, 2-methyl- | 75-28-5 | 58.12
2-Propanol | 67-63-0 | 60.10
n-Propylbenzene | 103-65-1 | 120.19
2-Propyl-methyl penatanoic acid | 31113-56-1 | 158.24
1-Propynylbenzene | 673-32-5 | 116.16
Pyrene | 129-00-0 | 202.25
Pyrene, 1-methyl- | 2381-21-7 | 216.28
Stigmasta-5,24(28)-dien-3-ol | 17605-67-3 | 412.70
Styrene | 100-42-5 | 104.15
1,1,2,2-Tetrachloroethane | 79-34-5 | 167.84
Tetrachloroethene | 127-18-4 | 165.82
Tetracosane | 646-31-1 | 338.66
Tetradecane | 629-59-4 | 198.39
Tetradecane, 1-chloro- | 2425-54-9 | 232.84
Tetradecanoic Acid | 544-63-8 | 228.37
Tetrahydrofuran | 109-99-9 | 72.11
Tetratriacontane | 14167-59-0 | 478.93
Toluene | 108-88-3 | 92.14
Triacontane | 638-68-6 | 422.82
1,2,4-Trichlorobenzene | 120-82-1 | 181.44
1,1,1-Trichloroethane | 71-55-6 | 133.40
1,1,2-Trichloroethane | 79-00-5 | 133.40
Trichloroethylene | 79-01-6 | 131.38
2,4,5-Trichlorophenol | 95-95-4 | 197.44
2,4,6-Trichlorophenol | 88-06-2 | 197.44
Trichlorotrifluoroethane | 76-13-1 | 187.37
Tricosane | 638-67-5 | 324.63
Tridecane | 629-50-5 | 184.37
2,3,6-Trimethylanisole | 21573-36-4 | 150.22
1,2,4-Trimethylbenzene | 95-63-6 | 120.19
1,3,5-Trimethylbenzene | 108-67-8 | 120.19
2,2,7-Trimethyl-3-octyne | 55402-13-6 | 152.28
2,4,4-Trimethylpentene | 107-40-4 | 112.22
Tritriacontane | 630-05-7 | 464.90
TXIB | 6846-50-0 | 286.41
Undecane | 1120-21-4 | 156.31
Undecane, 2,6-dimethyl- | 17301-23-4 | 184.37
Undecane, 4,6-dimethyl- | 17312-82-2 | 184.37
Undecane, 5,6-dimethyl- | 17615-91-7 | 184.37
Undecane, 3-methyl- | 1002-43-3 | 170.34
Undecane, 4-methyl- | 2980-69-0 | 170.34
Vinyl Acetate | 108-05-4 | 86.09
Vinyl Chloride | 75-01-4 | 62.50
m-Xylene | 108-38-3 | 106.17
o-Xylene | 95-47-6 | 106.17
p-Xylene | 106-42-3 | 106.17

^a^ For references used please refer to Table 1 in Perkins et al.^1^