# Appendix A Individual and Mixtures of Standards Procured to Identify Crumb Rubber Constituents

Table A-1 Individual Standards Procured^a^

Compound | Used For^b^ | Lot No. (Supplier, City, State) | CAS No. | Date Received | Amount Received | Vendor Purity (%) | Appearance | Storage Condition
1,2,4-Trimethylbenzene | 4 | MKBJ6229V (Sigma-Aldrich, Milwaukee, WI) | 95-63-6 | 6/29/17 | 25 mL | 98.8 | Colorless Liquid | Ambient
1,4-Dimethylnaphthalene | 1,2 | SZBE010XV SZBE083XV (Sigma-Aldrich, Milwaukee, WI) | 571-58-4 | 5/6/2016 | 100 mg 100 mg | 95.0 97.0 | Liquid | Ambient
1-Chlorooctadecane | 2 | XA12629 (Sigma-Aldrich, Milwaukee, WI) | 3386-33-2 | 5/6/2016 | 1 mL | 99.6 | Solution | 2ºC to 8ºC
1-Methoxy-2-Propanol | 1 | BCBL3411V (Sigma-Aldrich, Milwaukee, WI) | 107-98-2 | 2/8/2016 | 5 mL | 99.8 | Colorless Liquid | Ambient
1-Methylnapthalene | 1,2 | XA13461V (Sigma-Aldrich, Milwaukee, WI) | 90-12-0 | 5/6/2016 | 2 mL | 98.4 | Liquid | 2ºC to 8ºC
2-(Morpholinothio)-benzothiazole | 1,2 | B02308158 (Sigma-Aldrich, Milwaukee, WI) | 102-77-2 | 2/10/2016 | 1 g | Not Provided | Not Provided | Ambient
2,4,4-Trimethyl-1-pentene | 1,2,4 | MKBV5694V (Sigma-Aldrich, Milwaukee, WI) | 107-39-1 | 4/26/2016 | 100 g | 99 | Colorless Liquid | Ambient
2-Ethylnaphthalene | 1,2 | STBD0765V( Sigma-Aldrich, Milwaukee, WI) | 939-27-5 | 5/6/2016 | 5 g | 99.9 | Colorless Liquid | Ambient
2-Furaldehyde | 1,2 | SHBG2086V (Sigma-Aldrich, Milwaukee, WI) | 98-01-1 | 5/4/2016 | 5 mL | 99.8 | Very Light Yellow Liquid | Ambient
2-Hydroxybenzothiazole | 1,2,4 | STBD4107 (Sigma-Aldrich, Milwaukee, WI) | 934-34-9 | 2/8/2016 | 5 g | 99.1 | Faint Beige Powder | Ambient
2-Mercaptobenzothiazole | 4 | MKBZ5040V (Sigma-Aldrich, Milwaukee, WI) | 149-30-4 | 6/29/17 | 10 g | 99.9 | Light Yellow Powder | Ambient
2-Methylnapthalene | 1,2,4 | XA13611V (Sigma-Aldrich, Milwaukee, WI) | 91-57-6 | 5/6/2016 | 2 mL | 98.8 | Liquid | 2ºC to 8ºC
3-Buten-2-one | 1 | MKBP70746V (Sigma-Aldrich, Milwaukee, WI) | 78-94-4 | 5/6/2016 | 5 mL | 98.5 | Colorless Liquid | 2ºC to 8ºC
3-Ethyltoluene | 1,2,4 | STBD6464V (Sigma-Aldrich, Milwaukee, WI) | 620-14-4 | 5/6/2016 | 10 g | 99.7 | Colorless Liquid | Ambient
3-Methylfuran | 1 | B02323174 (Sigma-Aldrich, Milwaukee, WI) | 930-78-8 | 5/4/2016 | 100 mg | Not Provided | Liquid | Ambient
3-Methylhexane | 1,2 | MKBW2372V (Sigma-Aldrich, Milwaukee, WI) | 589-34-4 | 4/26/2016 | 5 g | 99.8 | Colorless Liquid | Ambient
4-tert-Octylphenol | 1,2,4 | MKBT8005 (Sigma-Aldrich, Milwaukee, WI) | 140-66-9 | 2/8/2016 | 500 mg | 98.7 | Not Provided | Ambient
5-Methyl-2-Hexanone | 1,2,4 | SHBC3669V (Sigma-Aldrich, Milwaukee, WI) | 110-12-3 | 5/6/2016 | 1 L | 98.75 | Colorless Liquid | Ambient
Acetaldehyde | 1 | LC17886V (Sigma-Aldrich, Milwaukee, WI) | 75-07-0 | 2/8/2016 | 1 mL | 99.9 | Colorless Liquid | 2ºC to 8ºC
Aniline | 1,2,3,4 | SHBG6394V (Sigma-Aldrich, Milwaukee, WI) | 62-53-3 | 4/1/2016 | 5 mL | 100 | Faint Yellow Liquid | Ambient
Benzothiazole | 1,2,3,4 | BCBP5624V (Sigma-Aldrich, Milwaukee, WI) | 95-16-9 | 2/8/16 6/1/16 9/6/16 | 200 mg 200 mg 300 mg | 99.7 | Light-Brown-Yellow Liquid | Ambient
Bis-2-ethylhexyl Phthalate | 4 | BCBL8383V (Sigma-Aldrich, Milwaukee, WI) | 117-81-7 | 6/29/17 | 100 mg | 99.6 | Not Provided | Ambient
Bisphenol P | 3,4 | BCBN1660V (Sigma-Aldrich, St. Louis, MO) | 2167-51-3 | 6/29/17 | 200 mg | 99.9% | White powder | Ambient
Butylated Hydroxyanisole | 1,2 | BCBN8023V (Sigma-Aldrich, Milwaukee, WI) | 25013-16-5 | 2/8/2016 | 500 mg | 99.9 | White Crystals | Ambient
Butylated Hydroxytoluene | 1,2,4 | LRAA7701 (Sigma-Aldrich, Milwaukee, WI) | 128-37-0 | 4/1/2016 | 1 g | 99.9 | White Powder | Ambient
Butyraldehyde | 1 | SHBD8136V (Sigma-Aldrich, Milwaukee, WI) | 123-72-8 | 4/26/2016 | 100 mL | 99.86 | Colorless Liquid | Ambient
Crotonaldehyde | 1,2 | BCBM3428V (Sigma-Aldrich, Milwaukee, WI) | 123-73-9 | 4/26/2016 | 5 mL | 99.7 | Colorless Liquid | 2ºC to 8ºC
Cyclohexanone | 1,2,4 | BCBL8626V (Sigma-Aldrich, Milwaukee, WI) | 108-94-1 | 4/1/2016 | 3 mL | 99.98 | Colorless Liquid | Ambient
Cyclohexene | 1 | BCBP8188V (Sigma-Aldrich, Milwaukee, WI) | 110-83-8 | 4/26/2016 | 5 mL | 99.7 | Colorless Liquid | Ambient
Dicyclohexylamine | 2,4 | MKBB9424V (Sigma-Aldrich, Milwaukee, WI) | 101-83-7 | 5/6/2016 | 5 g | 99.4 | Colorless Liquid | Ambient
Diphenylamine | 2,4 | MKBV3210V (Sigma-Aldrich, Milwaukee, WI) | 122-39-4 | 4/26/2016 | 5 g | 100 | White Crystals | Ambient
Ethylene Glycol Butyl Ether (2-Butoxyethanol) | 1 | BCBN8459V (Sigma-Aldrich, Milwaukee, WI) | 111-76-2 | 2/8/2016 | 5 mL | 99.6 | Colorless Liquid | Ambient
Fluorene | 4 | BCBS0780V (Sigma-Aldrich, Milwaukee, WI) | 86-73-7 | 6/29/17 | 100 mg | 98.7% | Not Provided | Ambient
Hexadecane | 1,2,3 | BCBQ7425V (Sigma-Aldrich, Milwaukee, WI) | 544-76-3 | 2/8/2016 | 5 mL | 99.9 | Colorless Liquid | Ambient
Hexamethylcyclotrisiloxane | 1,2,3 | BCBM4918V (Sigma-Aldrich, Milwaukee, WI) | 541-05-9 | 4/1/2016 | 100 mg | 99.8 | White Crystalline Chunks | Ambient
Hexanal | 1,2,4 | BCBQ1155V (Sigma-Aldrich, Milwaukee, WI) | 66-25-1 | 2/8/2016 | 2 mL | 98.1 | Colorless Liquid | Ambient
Methyl Ethyl Ketone (MEK) | 1,2 | P500207 (Sigma-Aldrich, Milwaukee, WI) | 78-93-3 | 2/8/2016 | 3.6 mL | 99.7 | Clear Liquid | Ambient
m-Xylene | 4 | BCBS5438V (Sigma-Aldrich, Milwaukee, WI) | 108-38-3 | 4/25/17 | 5 mL | 100% | Colorless liquid | Ambient
Methyl Isobutyl Ketone (MIK) | 1,2,3 | LRAA4472 (Sigma-Aldrich, Milwaukee, WI) | 108-10-1 | 2/8/2016 | 3.6 mL | 99.9 | Clear Liquid | Ambient
Methylcyclohexane | 1,2 | BCBQ6849V (Sigma-Aldrich, Milwaukee, WI) | 108-87-2 | 4/26/2016 | 2 mL | 99.6 | Colorless Liquid | Ambient
N-(1,3,-Dimethylbutyl)-N’-phenyl-p-phenylenediamine (6PPD) | 2,3 | B02323173 (Sigma-Aldrich, Milwaukee, WI) | 793-24-8 | 5/4/2016 | 500 mg | Not Provided | Black Powder | Ambient
Naphthalene | 4 | BCBR2099V (Sigma-Aldrich, Milwaukee, WI) | 91-20-3 | 8/30/2016 | 1 g | 99.9 | White Crystals | Ambient
N-Nitrosodimethylamine | 1 | LC14356V (Sigma-Aldrich, Milwaukee, WI) | 62-75-9 | 2/8/2016 | 1 mL | 99.9 | Not Provided | 2ºC to 8ºC
N-Nitrosodiphenylamine | 1 | LC17695V (Sigma-Aldrich, Milwaukee, WI) | 86-30-6 | 2/8/2016 | 1,000 mg | 98.1 | Brownish-Yellow Fine Crystals | Ambient
N-tert-Butyl-2-benzothiazolesulfenamide | 1,2 | 10119609 (Alpha Aesar,Ward Hill, MA) | 107-98-2 | 2/8/2016 | 50 g | 97.4 | Pale Cream Powder | Ambient
n-tert-Butylformamide | 1,2 | 1447853V (Sigma-Aldrich, Milwaukee, WI) | 2425-74-3 | 4/1/2016 | 25 g | 99.9 | Colorless Clear Liquid | Ambient
Phenol | 1,2,4 | STBG0464V (Sigma-Aldrich, Milwaukee, WI) | 108-95-2 | 5/4/2016 | 100 g | >99.9 | White Crystals | Ambient
Phthalamide | 2 | MKBB9424V (Sigma-Aldrich, Milwaukee, WI) | 85-41-6 | 5/6/2016 | 1 g | 99.9 | Beige Flakes | Ambient
Phthalimide | 4 | MKBW6020V (Sigma-Aldrich, Milwaukee, WI) | 85-41-6 | 8/22/2016 | 50 g | 99.8 | White Powder | Ambient
Propylene Glycol (1,2-Propanediol) | 1 | BCBQ0887V (Sigma-Aldrich, Milwaukee, WI) | 57-55-6 | 2/8/2016 | 5 mL | 99.99 | Colorless Viscous Liquid | Ambient
Pyrene | 4 | BCBR5529V (Sigma-Aldrich, Milwaukee, WI) | 129-00-0 | 6/29/17 | 100 mg | 99.2 | Not Provided | Ambient
Styrene | 4 | LC26706V (Sigma-Aldrich, Milwaukee, WI) | 100-42-5 | 9/1/17 | 1 g | 99.9 | Colorless Liquid | Ambient
tert-Butylamine | 1 | SHBG2764V (Sigma-Aldrich, Milwaukee, WI) | 75-64-9 | 4/1/2016 | 100 mL | 99.99 | Colorless Liquid | Ambient
Tetraethylthiuram Disulfide | 2 | BCBL7406V (Sigma-Aldrich, Milwaukee, WI) | 97-77-8 | 2/8/2016 | 50 g | 99.4 | Faint Beige Powder | Ambient
Tetramethylthiuram Disulfide | 2 | STBF1299V (Sigma-Aldrich, Milwaukee, WI) | 137-26-8 | 2/8/2016 | 5 g | >99.9 | White Powder | Ambient
Tetramethylthiuram Monosulfide | 2 | SHBC3940V (Sigma-Aldrich, Milwaukee, WI) | 97-74-5 | 2/8/2016 | 100 g | 97 | Yellow Powder | Ambient
Toluene | 3,4 | BCBR9283V (Sigma-Aldrich, Milwaukee, WI) | 108-88-3 | 4/25/17 | 5 mL | 99.91% | Colorless Liquid | Ambient
Trans-1,2-Dimethylcyclohexane | 1,2 | 12222ASV (Sigma-Aldrich, Milwaukee, WI) | 6876-23-9 | 4/26/2016 | 5 g | 99.8 | Colorless Liquid | Ambient
Trans-Cinnamaldehyde (3-phenyl-2propanal) | 1,2 | BCBP7078V (Sigma-Aldrich, Milwaukee, WI) | 14371-10-9 | 2/8/2016 | 100 mg | 96.1 | Green-Yellow Liquid | Ambient
Tetracosane | 4 | MKBZ5406V (Sigma-Aldrich, St. Louis, MO) | 646-31-1 | 6/29/17 | 25 g | 99.8% | White Crystals | Ambient
Tetratriacontane | 4 | BCBV2796 (Sigma-Aldrich, St. Louis, MO) | 14167-59-0 | 6/29/17 | 1 g | 99.4% | White Flakes | Ambient
Tricosane | 4 | MKBX1642V (Sigma-Aldrich, Milwaukee, WI) | 638-68-5 | 8/30/2016 | 1 g | 99.6 | White Crystals | Ambient

^a^ Information from the vendors certificate of analysis.

^b^ 1 = Headspace GC/MS Characterization, 2 = Liquid Injection GC/MS Characterization, 3 = LC/MS Characterization, 4 = Bioaccessibility and Size Fractionation Analyses.

Table A-2 Standards Mixes Procured^a, b^

Mixture | Used For^c^ | Lot No. (Supplier, City, State) | Date Received | Amount Received (mL) | Vendor Purity (%) | | Appearance | | Storage Condition
EPA VOC Mix 1 | 1,2 | LC09299V (Sigma-Aldrich, Milwaukee, WI) | 2/8/16 | 3 | | N/A | | Not Provided | 2ºC to 8ºC
EPA VOC Mix 2 | 1,2 | LC09300V (Sigma-Aldrich, Milwaukee, WI) | 2/8/16 | 3 | | N/A | | Not Provided | 2ºC to 8ºC
EPA VOC Mix 3 | 1,2 | XA18188V (Sigma-Aldrich, Milwaukee, WI) | 2/8/16 | 3 | | N/A | | Not Provided | 2ºC to 8ºC
EPA VOC Mix 4 | 1 | XA16770V (Sigma-Aldrich, Milwaukee, WI) | 2/10/16 | 3 | | N/A | | Not Provided | 2ºC to 8ºC
EPA VOC Mix 5 | 1 | LC09303V (Sigma-Aldrich, Milwaukee, WI) | 2/8/16 | 3 | | N/A | | Not Provided | 2ºC to 8ºC
EPA VOC Mix 6 | 1 | LC16135V (Sigma-Aldrich, Milwaukee, WI) | 2/8/16 | 3 | | N/A | | Not Provided | 2ºC to 8ºC
Phthalates in Methanol | 2 | SRM 3074 (Sigma-Aldrich, Milwaukee, WI) | 2/15/16 | 6 | | N/A | | Not Provided | Ambient
C7–C30 Saturated Alkanes | 1,2 | XA17133V (Sigma-Aldrich, Milwaukee, WI) | 4/26/16 | 2 | | N/A | | Not Provided | 2ºC to 8ºC
Multicomponent Alcohol Mix-100 | 1,2 | FN03251502 (Sigma-Aldrich, Milwaukee, WI) | 4/25/16 | 2.4 | | N/A | | Not Provided | 2ºC to 8ºC
PAH Analyte Mix | 2 | EN151214002 (SPEX Certiprep, Metuchen, NJ) | 7/8/16 | 2 | | N/A | | Liquid | Ambient
EPA 610 PAH Mix | 4 | XA21638V (Sigma-Aldrich, Milwaukee, WI) | 8/15/16 | 6 | | N/A | | Liquid | 2ºC to 8ºC

^a^ See Tables A-3 through A-13 for composition of each mixture.

^b^ Information from the vendors certificate of analysis.

^c^ 1 = Headspace GC/MS Characterization, 2 = Liquid Injection GC/MS Characterization, 3 = LC/MS Characterization, 4 = Bioaccessibility and Size Fractionation Analyses.

Table A-3 EPA VOC Mix 1 Components

Compound | Lot No. | CAS No. | Analytical Conc. (μg/mL)
sec-Butylbenzene | LB77150 | 135-98-8 | 1962.7
tert-Butylbenzene | LB40373 | 98-06-6 | 1956.2
Chlorobenzene | LB93949 | 109-90-7 | 1977.3
2-Chlorotoluene | LB01464 | 95-49-8 | 1947.3
4-Chlorotoluene | LB02742 | 106-43-4 | 2008.6
Cumene | LB89580 | 98-82-8 | 1958.6
1,2-Dichlorobenzene | LB58923 | 95-50-1 | 1953.9
1,3-Dichlorobenzene | LB68066 | 541-73-1 | 1950.8
1,4-Dichlorobenzene | LB90630 | 106-46-7 | 1957.0
n-Propylbenzene | LB69017 | 103-65-1 | 2070.6
o-Xylene | LB92424 | 95-47-6 | 1933.4
p-Xylene | LB86113 | 106-42-3 | 1984.3

Table A-4 EPA VOC Mix 2 Components

Compound | Lot No. | CAS No. | Analytical Conc. (μg/mL)
Benzene | LC03683 | 71-43-2 | 1878.0
Bromobenzene | LB99843 | 108-86-1 | 1935.2
n-Butylbenzene | LB81630 | 104-51-8 | 1947.3
Ethylbenzene | LB69556 | 100-41-4 | 1960.5
p-Isopropyltoluene | LB40003 | 99-87-6 | 1898.7
Naphthalene | LB89929 | 91-20-3 | 1951.3
Styrene | LB86229 | 100-42-5 | 1946.9
Toluene | LB94376 | 108-88-3 | 1922.4
1,2,3-Trichlorobenzene | LA50762 | 87-61-6 | 1949.6
1,2,4-Trichlorobenzene | LB48083 | 120-82-1 | 1960.2
1,2,4-Trimethylbenzene | LB97224 | 95-63-6 | 1911.1
1,3,5-Trimethylbenzene | LB82157 | 108-67-8 | 1938.3
m-Xylene | LB87531 | 108-38-3 | 1941.2

Table A-5 EPA VOC Mix 3 Mix Components

Compound | Lot No. | CAS No. | Analytical Conc. (μg/mL)
1,2-Dibromo-3-Chloropropane | LB06608 | 96-12-8 | 2008.7
1,2-Dibromoethane | LB42792 | 106-93-4 | 2000.0
1,2-Dichloroethane | LB74294 | 107-06-2 | 2005.7
1,2-Dichloropropane | LC14320 | 78-87-5 | 2030.8
1,3-Dichloropropane | LC10811 | 142-28-9 | 2025.3
1,1-Dichloropropene | LC11148 | 563-58-6 | 1837.7
cis-1,3-Dichloroprepene | LB96292 | 10061-01-5 | 2044.2
trans-1,3-Dichloropropene | LC11733 | 10061-02-6 | 2004.4
Hexachlorobutadiene | LB75566 | 87-68-3 | 2006.7
1,1,1,2-Tetrachloroethane | LC14810 | 630-20-6 | 2017.2
1,1,2,2-Tetrachloroethane | LB51327 | 79-34-5 | 2052.4
1,1,2-Trichloroethane | LB87978 | 79-00-5 | 1993.0
Trichloroethene | LB56674 | 79-01-6 | 1977.5
1,2,3-Trichloropropane | LB82841 | 96-18-4 | 2016.0

Table A-6 EPA VOC Mix 4 Mix Components

Compound | Lot No. | CAS No. | Analytical Conc. (μg/mL)
Bromochloromethane | LB39040 | 74-97-5 | 1953.3
Bromoform | LB99100 | 75-25-2 | 1990.6
Carbon Tetrachloride | LA55583 | 56-23-5 | 1949.4
Chloroform | LB97804 | 67-66-3 | 2000.0
Dibromomethane | LB81118 | 74-95-3 | 2055.2
1,1-Dichloroethane | LB68167 | 75-34-3 | 1842.0
2,2-Dichloropropane | LB90123 | 594-20-7 | 1932.9
Tetrachloroethene | LB67182 | 127-18-4 | 1977.4
1,1,1-Trichloroethane | LC06533 | 71-55-6 | 1976.8

Table A-7 EPA VOC Mix 5 Mix Components

Compound | Lot No. | CAS No. | Analytical Conc. (μg/mL)
Bromodichloromethane | LB78267 | 75-27-4 | 2000.0
Dibromochloromethane | LB89245 | 124-48-1 | 2016.6
1,1-Dichloroethylene | LC08188 | 75-34-4 | 1822.1
cis-1,2-Dichloroethylene | LB73428 | 156-59-2 | 1967.2
trans-1,2-Dichloroethylene | LB82639 | 156-60-5 | 1914.2
Methylene Chloride | LB87418 | 75-09-2 | 1968.9

Table A-8 EPA VOC Mix 6 Mix Components

Compound | Lot No. | CAS No. | Analytical Conc. (μg/mL)
Bromomethane | LB22203 | 74-83-9 | 2030
Chloroethane | LB55667 | 75-00-3 | 2029
Chloromethane | LB64986 | 74-87-3 | 2063
Dichlorodifluoromethane | LB68837 | 75-71-8 | 1867
Trichlorofluoromethane | LA91320 | 75-69-4 | 2086
Vinyl Chloride | LB66643 | 75-01-4 | 2031

Table A-9 Phthalates in Methanol Components

Compound | Lot No. | CAS No. | Analytical Conc. (mg/L)
Dimethylphthalate | – | 131-11-3 | 44
Diethylphthalate | – | 84-66-2 | 40.7
Di-n-butylphthalate | NA^a^ | 84-74-2 | 40.5
Benzylbutylphthalate | – | 85-68-7 | 41.3
Bis(2-ethylhexyl)phthalate | – | 117-81-7 | 46.4
Di-n-octylphthalate | – | 117-84-0 | 38.2

^a^ Separate lot numbers for constituents not provided.

Table A-10 C7–C30 Saturated Alkanes

Compound | Lot No. | CAS No. | Analytical Conc. (μg/mL)
n-Decane | LC07947 | 124-18-5 | 1025.3
n-Docosane | LC11073 | 629-97-0 | 1018.5
n-Dodecane | LC08158 | 112-40-3 | 1025.1
n-Eicosane | LB97320 | 112-95-8 | 1016.7
n-Heneicosane | LB85393 | 629-94-7 | 1017.1
n-Heptacosane | LC11618 | 593-49-7 | 1015.7
n-Heptadecane | LC12302 | 629-78-7 | 1023.6
n-Heptane | LC07614 | 142-82-5 | 1028.0
n-Hexacosane | LC11398 | 630-01-3 | 1016.8
n-Hexadecane | LC02125 | 544-76-3 | 1021.0
n-Nonacosane | LC08881 | 630-03-5 | 1012.7
n-Nonadecane | LB30980 | 629-92-5 | 1018.1
n-Nonane | LC00219 | 111-84-2 | 1026.5
n-Octacosane | LB95341 | 630-02-4 | 1018.8
n-Octadecane | LB89629 | 593-45-3 | 1019.6
n-Octane | LB63797 | 111-65-9 | 1028.1
n-Pentacosane | LC15080 | 629-99-2 | 1016.8
n-Pentadecane | LC08640 | 629-62-9 | 1022.8
n-Tetracosane | LC13242 | 646-31-1 | 1018.9
n-Tetradecane | LC15053 | 629-59-4 | 1019.8
n-Triacontane | LC07823 | 638-68-6 | 1019.1
n-Tricosane | LB36889 | 638-67-5 | 1018.3
n-Tridecane | LC14314 | 629-50-5 | 1022.2
n-Undecane | LC08959 | 1120-21-4 | 1025.2

Table A-11 Multicomponent Alcohol Mix-100

Compound | Lot No. | CAS No. | Analytical Conc.(μg/mL)
Acetone | – | 67-64-1 | 101.4
Ethanol | FN03251502 | 64-17-5 | 103.4
Isopropanol | – | 67-63-0 | 102.2
Methanol | – | 67-56-1 | 102.3

Table A-12 PAH Analyte Mix

Compound | Lot No. | CAS No. | Analytical Conc. (μg/mL)
Acenaphthene | – | 83-32-9 | 2001
Acenaphthylene | – | 208-96-8 | 2001
Anthracene | – | 120-12-7 | 2001
Benz(a)anthracene | – | 56-55-3 | 1995
Benzo(a)pyrene | – | 50-32-8 | 2002
Benzo(b)fluoranthene | – | 205-99-2 | 2004
Benzo(g,h,i)perylene | – | 191-24-2 | 1996
Benzo(k)fluoranthene | NA^a^ | 207-08-9 | 1999
Chrysene | – | 218-01-9 | 2002
Dibenz(a,h,)anthracene | – | 53-70-3 | 1999
Fluoranthene | – | 206-44-0 | 2003
Fluorene | – | 86-73-7 | 2004
Indeno(1,2,3-c,d)pyrene | – | 193-39-5 | 2000
Naphthalene | – | 91-20-3 | 1995
Phenanthrene | – | 85-01-8 | 2000
Pyrene | – | 129-00-0 | 2007

^a^ Separate lot numbers for constituents not provided.

Table A-13 EPA 610 PAH Mix

Compound | Lot No. | CAS No. | Analytical Conc. (μg/mL)
Acenaphthene, CRM | LC15478 | 83-32-9 | 1059.6
Acenaphtylene, CRM | LC20622 | 208-96-8
Anthracene, CRM | LC20462 | 120-12-7 | 107.4
Benz(a)anthracene, CRM | LB94996 | 56-55-3 | 106.5
Benzo(a)pyrene, CRM | LC19497 | 50-32-8 | 111.5
Benzo(b)fluoranthene, CRM | LB89946 | 205-99-2 | 217.4
Benzo(ghi)perylene, CRM | LB96971 | 191-24-2 | 201.9
Benzo(k)fluoranthene, CRM | LB89276 | 207-08-9 | 107.8
Chrysene, CRM | LC20748 | 218-01-9 | 106.4
Dibenz(a,h)anthracene, CRM | LC20472 | 53-70-3 | 213.4
Fluoranthene, CRM | LC15477 | 206-44-0 | 215.9
Fluorene, CRM | LC15479 | 86-73-7 | 216.1
Indeno(1,2,3-C,D)pyrene, CRM | LC20473 | 193-39-5 | 107.0
Naphthalene, CRM | LC11683 | 91-20-3 | 1052.7
Phenanthrene, CRM | LC18318 | 85-01-8 | 106.7
Pyrene, CRM | LC15727 | 129-00-0 | 99.3