# Publication Details

Publisher: National Toxicology Program

Publishing Location: Research Triangle Park, North Carolina

ISSN: 2473-4756

DOI: https://doi.org/10.22427/NTP-RR-1

Report Series: NTP Research Report Series

Report Series Number: 1

Official citation: National Toxicology Program (NTP). 2016. NTP research report on systematic literature review on the effects of fluoride on learning and memory in animal studies. Research Triangle Park, NC: National Toxicology Program. Research Report 1.