# Protocol Review

The protocol and design were evaluated by the reviewers listed below.

Emily Sena, Ph.D.

Coordinator of the Collaborative Approach to Meta-Analysis and Review of Animal Data in Experimental Studies

Department of Neurology and Translational Neuroscience

University of Edinburgh

Edinburgh, Scotland

Staff

National Industrial Chemicals Notification and Assessment Scheme

Department of Health

Australian Government

Canberra, Australia