# Peer Review

The research report, Systematic Literature Review on the Effects of Fluoride on Learning and Memory in Animal Studies, was evaluated by the reviewers listed below. These reviewers served as independent scientists, not as representatives of any institution, company, or governmental agency. In this capacity, reviewers determined if the design and conditions of these NTP studies were appropriate and ensured that this NTP Research Report presented the experimental results and conclusions fully and clearly.

## Peer Reviewers

- Charles Vorhees, Ph.D.
  Division of Neurology
  Cincinnati Children’s Hospital Medical Center
  Cincinnati, Ohio, USA
- Russell Carr, Ph.D.
  Center for Environmental Health Sciences
  Department of Basic Sciences College of Veterinary Medicine
  Mississippi State University
  Starkville, Mississippi, USA