# Collaborators

- Division of the National Toxicology Program, National Institute of Environmental Health Sciences, Research Triangle Park, North Carolina, USA
  Contributed to conception or design and contributed to drafting of protocol
  Jean Harry, Ph.D., Project Co-lead
  Kristina Thayer, Ph.D., Project Co-lead
  Mamta Behl, Ph.D.
  John Bucher, Ph.D.
  Andrew Shapiro, M.S.
- Contributed to drafting of report
  Jean Harry, Ph.D., Project Co-lead
  Kristina Thayer, Ph.D., Project Co-lead
- Critically reviewed draft report and figures
  Mamta Behl, Ph.D.
  John Bucher, Ph.D.
  Stephanie Holmgren, M.S.
  Andrew Shapiro, M.S.
- Retrieved and managed references
  Stephanie Holmgren, M.S.
- Assessed risk of bias
  Jean Harry, Ph.D.
  Kristina Thayer, Ph.D.
- ICF, Durham, North Carolina, USA
  Critically reviewed draft report and figures
  Pamela Hartman, M.E.M., Technical Lead
  Greg Carter, M.E.M., Co-Lead Work Assignment Manager
  Cara Henning, Ph.D., Co-Lead Work Assignment Manager
- Extracted data
  Pamela Hartman, M.E.M.
- Developed visualizations
  Pamela Hartman, M.E.M.