# References

Bai J Chen Y Liu Q-b 2010. Learning and memory obstacles and changes in brain growth tissue inhibitors from brick tea fluoride and alminum poisoning of rats. Chinese Journal of Control of Endemic Diseases. 25(8734):161–163.
Balaji B Kumar EP Kumar A 2015. Evaluation of standardized Bacopa monniera extract in sodium fluoride-induced behavioural, biochemical, and histopathological alterations in mice. Toxicol Ind Health.31(1):18–30. 10.1177/0748233712468018 23222693
Balayssac D Richard D Authier N Nicolay A Jourdan D Eschalier A Coudoré F 2002. Absence of painful neuropathy after chronic oral fluoride intake in Sprague-Dawley and Lou/C rats. Neurosci Lett. 327(3):169–172. 10.1016/S0304-3940(02)00421-4 12113904
Banji D Banji OJ Pratusha NG Annamalai AR 2013. Investigation on the role of Spirulina platensis in ameliorating behavioural changes, thyroid dysfunction and oxidative stress in offspring of pregnant rats exposed to fluoride. Food Chem.140(1-2):321–331. 10.1016/j.foodchem.2013.02.076 23578649
Bǎran-Poesina V Negreș S Dobrescu D Dimcevici-Poesina N Dimcevici-Poesina A Feghiu A Soare T Militaru M 2013. Experimental pharmacological researches regarding the influence of sodium fluoride in allopathic and homeopathic doses on central nervous system’s performances. A correlation between behavioral response in classic maze test and morphological aspects of cerebral cortex. Farmacia. 61(4):781–799.
Bartos M Gumilar F Bras C Gallegos CE Giannuzzi L Cancela LM Minetti A 2015. Neurobehavioural effects of exposure to fluoride in the earliest stages of rat development. Physiol Behav. 147:205–212. 10.1016/j.physbeh.2015.04.044 25921949
Basha PM Rai P Begum S 2011. Fluoride toxicity and status of serum thyroid hormones, brain histopathology, and learning memory in rats: a multigenerational assessment. Biol Trace Elem Res. 144(1-3):1083–1094. 10.1007/s12011-011-9137-3 21755305
Basha PM Sujitha NS 2012. Combined impact of exercise and temperature in learning and memory performance of fluoride toxicated rats. Biol Trace Elem Res. 150(1-3):306–313. 10.1007/s12011-012-9489-3 22918786
Bataineh HN Nusier MK 2006. Impact of 12-week ingestion of sodium fluoride on aggression, sexual behavior, and fertility in adult male rats. Fluoride. 39(4):293–301.
Bera I Sabatini R Auteri P Flace P Sisto G Montagnani M Potenza MA Marasciulo FL Carratu MR Coluccia A 2007. Neurofunctional effects of developmental sodium fluoride exposure in rats. Eur Rev Med Pharmacol Sci.11(4):211–224. 17876956
Bhatnagar M Rao P Sushma J Bhatnagar R 2002. Neurotoxicity of fluoride: neurodegeneration in hippocampus of female mice. Indian J Exp Biol.40(5):546–554. 12622200
Broadbent JM Thomson WM Ramrakha S Moffitt TE Zeng J Foster Page LA Poulton R 2015. Community water fluoridation and intelligence: prospective study in New Zealand. Am J Public Health. 105(1):72–76. 10.2105/AJPH.2013.301857 24832151
California Office of Environmental Health Hazard Assessment (OEHHA). 2011. Meeting synopsis and slide presentations: Carcinogen identification committee meeting held on October 12, 2011. https://oehha.ca.gov/proposition-65/transcript-comment-presentation/meeting-synopsis-and-slide-presentations-carcinogen.https://oehha.ca.gov/proposition-65/transcript-comment-presentation/meeting-synopsis-and-slide-presentations-carcinogen.
Chen H, Geng D. 2011. The establishment and assessment of animal model of chronic fluorosis-induced cognitive dysfunction in rats. Acta Acad Med Xuzhou. (5):319-322.
Chioca LR Raupp IM Da Cunha C Losso EM Andreatini R 2008. Subchronic fluoride intake induces impairment in habituation and active avoidance tasks in rats. Eur J Pharmacol. 579(1-3):196–201. 10.1016/j.ejphar.2007.10.019 18001709
Choi AL Sun G Zhang Y Grandjean P 2012. Developmental fluoride neurotoxicity: a systematic review and meta-analysis. Environ Health Perspect. 120(10):1362–1368. 10.1289/ehp.1104912 22820538
Crawley JN 2007. What’s wrong with my mouse?: Behavioral phenotyping of transgenic and knockout mice. 2nd ed. John Wiley & Sons. 10.1002/0470119055
Dabeka RW Karpinski KF McKenzie AD Bajdik CD 1986. Survey of lead, cadmium and fluoride in human milk and correlation of levels with environmental and food factors. Food Chem Toxicol. 24(9):913–921. 10.1016/0278-6915(86)90318-2 3781438
Dong Y-T Wang Y Wei N Guan Z 2015 b. Expression of muscarinic acetylcholine receptors in the brain of rats with chronic fluorosis. Chinese Journal of Endemiology. 34(2):84–88.
Dong Y-T Wang Y Wei N Guan Z-Z 2015 a. Expression levels of brain muscarinic acetylcholine receptor in offspring rats of drinking-water borne fluorosis. Chinese Journal of Endemiology. 34(5):326–330.
Dong Y-T Wang Y Wei N Zhang Q-F Guan Z-Z 2015 c. Deficit in learning and memory of rats with chronic fluorosis correlates with the decreased expressions of M1 and M3 muscarinic acetylcholine receptors. Arch Toxicol. 89(11):1981–1991. 10.1007/s00204-014-1408-2 25417050
Dunipace AJ Brizendine EJ Zhang W Wilson ME Miller LL Katz BP Warrick JM Stookey GK 1995. Effect of aging on animal response to chronic fluoride exposure. J Dent Res. 74(1):358–368. 10.1177/00220345950740011201 7876430
EFSA 2012. EFSA Scientific Committee; Guidance on selected default values to be used by the EFSA Scientific Committee, Scientific Panels and Units in the absence of actual measured data. EFSA J. 10(3):2579.10.2903/j.efsa.2012.2579
Ekambaram P Paul V 2001. Calcium preventing locomotor behavioral and dental toxicities of fluoride by decreasing serum fluoride level in rats. Environ Toxicol Pharmacol. 9(4):141–146. 10.1016/S1382-6689(00)00063-6 11292576
Ekambaram P Paul V 2002. Modulation of fluoride toxicity in rats by calcium carbonate and by withdrawal of fluoride exposure. Pharmacol Toxicol. 90(2):53–58. 10.1034/j.1600-0773.2002.900201.x 12071426
Ekambaram P Paul V 2003. Effect of vitamin D on chronic behavioral and dental toxicities of sodium fluoride in rats. Fluoride. 36(3):189–197.
Ekstrand J Boreus LO de Chateau P 1981. No evidence of transfer of fluoride from plasma to breast milk. Br Med J (Clin Res Ed). 283(6294):761–762. 10.1136/bmj.283.6294.761 6791740
Ekstrand J Ehrnebo M 1979. Influence of milk products on fluoride bioavailability in man. Eur J Clin Pharmacol. 16(3):211–215. 10.1007/BF00562063 499322
Ekstrand J Ehrnebo M Boréus LO 1978. Fluoride bioavailability after intravenous and oral administration: importance of renal clearance and urine flow. Clin Pharmacol Ther. 23(3):329–337. 10.1002/cpt1978233329 627140
Ekstrand J Ziegler EE Nelson SE Fomon SJ 1994. Absorption and retention of dietary and supplemental fluoride by infants. Adv Dent Res. 8(2):175–180. 10.1177/08959374940080020701 7865072
El-lethey H Kamel M Shaheed I 2011. Perinatal exposure to sodium fluoride with emphasis on territorial aggression, sexual behaviour and fertility in male rats. Life Sci J. 8(2):686–694.
El-lethey HS Kamel MM 2011. Effects of black tea in mitigation of sodium fluoride potency to suppress motor activity and coordination in laboratory rats. J Am Sci. 7:243–254.
El-lethey HS Kamel MM Shaheed IB 2010. Neurobehavioral toxicity produced by sodium fluoride in drinking water of laboratory rats. J Am Sci. 6(5):54–63.
El-lethey HS Shaheed IB 2011. Potential health impact of black tea against Na-F-Induced alterations in territorial aggression, sexual behaviour and fertility of male rats. Life Sci J. 8:828–839.
Elliott L 1967. Lack of effect of administration of fluoride on the central nervous system of rats. Acta Pharmacol Toxicol (Copenh). 25(3):323–328. 10.1111/j.1600-0773.1967.tb01439.x 5630488
Flace P Benagiano V Vermesan D Sabatini R Inchingolo AM Auteri P Ambrosi G Tarullo A Cagiano R 2010. Effects of developmental fluoride exposure on rat ultrasonic vocalization, acoustic startle reflex and pre-pulse inhibition. Eur Rev Med Pharmacol Sci. 14(6):507–512. 20712257
Gao Q Liu Y Wu C Long Y Guan Z 2008 b. Effects of fluoride on learning and memory and cholinesterase activity in rat brains. Chinese Journal of Endemiology. 27:128–130.
Gao Q Liu Y-J Guan Z-Z 2009 a. Decreased learning and memory ability in rats with fluorosis: increased oxidative stress and reduced cholinesterase activity in the brain. Fluoride. 42(4):277.
Gao Q Liu Y-J Wu C-X Long Y-G Guan Z-Z 2008 a. Level of oxidative stress in rat brains and learning and memory function of rats with chronic fluorosis. Chinese Journal of Endemiology. 27(4):371–373.
Gao Y Liu L Young L Huan L Jin H 2009 b. Effects of learning and memory of fluoride and the antagonism of selenium in rats. Studies of Trace Elements and Health. 26:1–3.
Gopal K Saxena R Gupta G Rana M Agrawal D 2006. Fluoride induced alterations in neurobehavioural and cardiovascular responses in Rats. Journal of Advanced Zoology. 27(1):1.
Gui C-Z Ran L-Y Li J-P Guan Z-Z 2010. Changes of learning and memory ability and brain nicotinic receptors of rat offspring with coal burning fluorosis. Neurotoxicol Teratol. 32(5):536–541. 10.1016/j.ntt.2010.03.010 20381606
Guyatt G Oxman AD Akl EA Kunz R Vist G Brozek J Norris S Falck-Ytter Y Glasziou P DeBeer H 2011 a. GRADE guidelines: 1. Introduction-GRADE evidence profiles and summary of findings tables. J Clin Epidemiol. 64(4):383–394. 10.1016/j.jclinepi.2010.04.026 21195583
Guyatt GH Oxman AD Kunz R Brozek J Alonso-Coello P Rind D Devereaux PJ Montori VM Freyschuss B Vist G 2011 b. GRADE guidelines 6. Rating the quality of evidence—imprecision. J Clin Epidemiol. 64(12):1283–1293. 10.1016/j.jclinepi.2011.01.012 21839614
Guyatt GH Oxman AD Montori V Vist G Kunz R Brozek J Alonso-Coello P Djulbegovic B Atkins D Falck-Ytter Y 2011 c. GRADE guidelines: 5. Rating the quality of evidence—publication bias. J Clin Epidemiol. 64(12):1277–1282. 10.1016/j.jclinepi.2011.01.011 21802904
Hamilton M 1992. Water fluoridation: a risk assessment perspective. J Environ Health. 27–32.
Han H Du W Zhou B Zhang W Xu G Niu R Sun Z 2014. Effects of chronic fluoride exposure on object recognition memory and mRNA expression of SNARE complex in hippocampus of male mice. Biol Trace Elem Res. 158(1):58–64. 10.1007/s12011-014-9889-7 24488208
Haseman JK Bailer AJ Kodell RL Morris R Portier K 2001. Statistical issues in the analysis of low-dose endocrine disruptor data. Toxicol Sci. 61(2):201–210. 10.1093/toxsci/61.2.201 11353128
Higgins J, Green S.2011. Cochrane handbook for systematic reviews of interventions. Version 5.1. 0.http://handbook.cochrane.org/.
Hong J-H Ge Y-M Ning H-M 2005. Effects of high fluoride and low iodine on learning-memory and TchE of brain in offspring rats. China Preventive Medicine. 6:489–491.
Hooijmans CR Tillema A Leenaars M Ritskes-Hoitinga M 2010. Enhancing search efficiency by means of a search filter for finding all studies on animal experimentation in PubMed. Lab Anim. 44(3):170–175. 10.1258/la.2010.009117 20551243
Iheozor-Ejiofor Z Worthington HV Walsh T O’Malley L Clarkson JE Macey R Alam R Tugwell P Welch V Glenny AM 2015. Water fluoridation for the prevention of dental caries. Cochrane Database Syst Rev. (6):CD010856. 10.1002/14651858.CD010856.pub2 26092033
International Programme on Chemical Safety (IPCS). 2002. Fluorides. Environmental Health Criteria 227. Geneva, Switzerland: World Health Organization http://www.inchem.org/documents/ehc/ehc/ehc227.htm.
Jain A Mehta VK Chittora R Mahdi AA Bhatnagar M 2015. Melatonin ameliorates fluoride induced neurotoxicity in young rats: An In Vivo evidence. Asian Journal of Pharmaceutical and Clinical Research. 8(4):164–167.
Jetti R Raghuveer CV Mallikarjuna RC 2016. Protective effect of ascorbic acid and Ginkgo biloba against learning and memory deficits caused by fluoride. Toxicol Ind Health. 32(1):183–187. 10.1177/0748233713498460 24081631
Jiang C Zhang S Liu H Guan Z Zeng Q Zhang C Lei R Xia T Wang Z Yang L 2014 a. Low glucose utilization and neurodegenerative changes caused by sodium fluoride exposure in rat’s developmental brain. Neuromolecular Med. 16(1):94–105. 10.1007/s12017-013-8260-z 23982469
Jiang S Su J Yao S Zhang Y Cao F Wang F Wang H Li J Xi S 2014 b. Fluoride and arsenic exposure impairs learning and memory and decreases mGluR5 expression in the hippocampus and cortex in rats. PLoS One. 9(4):e96041. 10.1371/journal.pone.0096041 24759735
Kaminsky LS Mahoney MC Leach J Melius J Miller MJ 1990. Fluoride: benefits and risks of exposure. Crit Rev Oral Biol Med. 1(4):261–281. 10.1177/10454411900010040501 2129630
Kivrak Y 2012. Effects of fluoride on anxiety and depression in mice. Fluoride.45(3):302–306.
Krauth D Woodruff TJ Bero L 2013. Instruments for assessing risk of bias and other methodological criteria of published animal studies: a systematic review. Environ Health Perspect. 121(9):985–992. 10.1289/ehp.1206389 23771496
Li M Cui J Gao Y Zhang W Sun L Liu X Liu Y Sun D 2015. Pathological changes and effect on the learning and memory ability in rats exposed to fluoride and aluminum. Toxicol Res. 4(5):1366–1373. 10.1039/C5TX00050E
Liu F Ma J Zhang H Liu P Liu Y-P Xing B Dang Y-H 2014. Fluoride exposure during development affects both cognition and emotion in mice. Physiol Behav. 124:1–7. 10.1016/j.physbeh.2013.10.027 24184405
Liu W. 1989. Experimental study of behavior and cerebral morphology of rat pups generated by fluorotic female rat. Chinese Journal of Pathology. 18(4):290-292.
Liu Y-J Gao G Long Y-G Yu Y-N Guan Z 2011. Influence of chronic fluorosis on expression of phospho-Elk-1 in rat brains. Chinese Journal of Endemiology. 30(3):251–255.
Liu YJ Gao Q Wu CX Guan ZZ 2010. Alterations of nAChRs and ERK1/2 in the brains of rats with chronic fluorosis and their connections with the decreased capacity of learning and memory. Toxicol Lett. 192(3):324–329. 10.1016/j.toxlet.2009.11.002 19900517
Liu YJ Gao Q Wu CX Long YG Guan ZZ 2009. Modified expression of extracellular signal-regulated protein kinase signal transduction in rat brains and changed capacity of learning and memory of rats with chronic fluorosis. Chinese Journal of Endemiology. 28(1):32–35.
Ma J, Liu F, Liu P, Dong YY, Chu Z, Hou TZ, Dang YH. 2015. Impact of early developmental fluoride exposure on the peripheral pain sensitivity in mice. Int J Dev Neurosci. 47(Pt B):165-171. 10.1016/j.ijdevneu.2015.09.005 10.1016/j.ijdevneu.2015.09.005
Mullenix PJ Denbesten PK Schunior A Kernan WJ 1995. Neurotoxicity of sodium fluoride in rats. Neurotoxicol Teratol. 17(2):169–177. 10.1016/0892-0362(94)00070-T 7760776
National Research Council (NRC). 1993. Health effects of ingested fluoride. Washington (DC): National Academies Press.
National Research Council (NRC). 2006. Committee on Fluoride in Drinking Water, Board on Environmental Studies and Toxicology. Fluoride in drinking water: a scientific review of EPA’s standards. Washington (DC): National Academies Press.
National Toxicology Program (NTP).2015a. Handbook for conducting a literature-based health assessment using Office of Health Assessment and Translation (OHAT) approach for systematic review and evidence integration. National Institute of Environmental Health Sciences, Division of the National Toxicology Program, Office of Health Assessment and Translation (OHAT).https://ntp.niehs.nih.gov/pubhealth/hat/review/index-2.html.
National Toxicology Program (NTP). 2015 b. OHAT risk of bias tool. https://ntp.niehs.nih.gov/pubhealth/hat/review/index-2.html.
Niu R Liu S Wang J Zhang J Sun Z Wang J 2014. Proteomic analysis of hippocampus in offspring male mice exposed to fluoride and lead. Biol Trace Elem Res. 162(1-3):227–233. 10.1007/s12011-014-0117-2 25260320
Niu R Sun Z Cheng Z Li Z Wang J 2009. Decreased learning ability and low hippocampus glutamate in offspring rats exposed to fluoride and lead. Environ Toxicol Pharmacol. 28(2):254–258. 10.1016/j.etap.2009.04.012 21784012
Niu R Sun Z Wang J Cheng Z Wang J 2008. Effects of fluoride and lead on locomotor behavior and expression of nissl body in brain of adult rats. Fluoride. 41(4):276–282.
Ophaug RH Singer L Harland BF 1980. Estimated fluoride intake of average two-year-old children in four dietary regions of the United States. J Dent Res. 59(5):777–781. 10.1177/00220345800590050501 6928866
Paul V Ekambaram P Jayakumar AR 1998. Effects of sodium fluoride on locomotor behavior and a few biochemical parameters in rats. Environ Toxicol Pharmacol. 6(3):187–191. 10.1016/S1382-6689(98)00033-7 21781893
Pereira M Dombrowski PA Losso EM Chioca LR Da Cunha C Andreatini R 2011. Memory impairment induced by sodium fluoride is associated with changes in brain monoamine levels. Neurotox Res. 19(1):55–62. 10.1007/s12640-009-9139-5 19957215
Raghu J Raghuveer VC Rao MC Somayaji NS Babu PB 2013. The ameliorative effect of ascorbic acid and Ginkgo biloba on learning and memory deficits associated with fluoride exposure. Interdiscip Toxicol. 6(4):217–221. 10.2478/intox-2013-0032 24678261
Reddy MM Karnati PR 2015. Protective effects of aqueous extract of fruit pulp of Tamarindus indica on motor activity and metabolism of the gastrocnemius muscle of rats treated with fluoride. International Journal of Toxicological and Pharmacological Research. 7(5):241–246.
Rumiantsev GI Novikov SM Mel’nikova NN Levchenko NI Kozeeva EE 1988. [Experimental study of the biological effect of salts of hydrofluosilicic acid]. Gig Sanit. (11):80–82. 3243463
Sarkozi K Horvath E Vezer T Papp A Paulik E 2015. Behavioral and general effects of subacute oral arsenic exposure in rats with and without fluoride. Int J Environ Health Res. 25(4):418–431. 10.1080/09603123.2014.958138 25260113
Scientific Committee on Health and Environmental Risks (SCHER). 2011. European Commission Directorate-General for Health and Consumers, Scientific Committees. Critical review of any new evidence on the hazard profile, health effects, and human exposure to fluoride and the fluoridating agents of drinking water. https://ec.europa.eu/health/scientific_committees/environmental_risks/docs/scher_o_139.pdf.http://ec.europa.eu/health/scientific_committees/environmental_risks/docs/scher_o_139.pdf.
Shen X Zhang Z Xu X 2004. Effect of iodine and selenium on learning memory impairment induced by fluorosis and blood biochemical criterion of rats. Occupation and Health. 1:6–8.
Shen YW Taves DR 1974. Fluoride concentrations in the human placenta and maternal and cord blood. Am J Obstet Gynecol.119(2):205–207. 10.1016/0002-9378(74)90035-0 4823388
Shulman ER Vallejo M 1990. Effect of gastric contents on the bioavailability of fluoride in humans. Pediatr Dent. 12(4):237–240. 2077500
Spak CJ Ekstrand J Zylberstein D 1982. Bioavailability of fluoride added by baby formula and milk. Caries Res. 16(3):249–256. 10.1159/000260605 6954003
Sun Z Liu F Wu Ln Lu Y Yu D 2008. Effects of high fluoride drinking water on the cerebral function of mice. Fluoride. 41(2):148–151.
Sutton M, Kiersey R, Farragher L, Long J. 2015. Health effects of water fluoridation: An evidence review. Ireland: Republic of Ireland Department of Health. https://www.hrb.ie/uploads/tx_hrbpublications/Health_Effects_of_Water_Fluoridation.pdf
Trautner K Einwag J 1989. Influence of milk and food on fluoride bioavailability from NaF and Na2FPO3 in man. J Dent Res. 68(1):72–77. 10.1177/00220345890680011201 2910959
Turner CH Hasegawa K Zhang W Wilson M Li Y Dunipace AJ 1995. Fluoride reduces bone strength in older rats. J Dent Res. 74(8):1475–1481. 10.1177/00220345950740080701 7560402
U.S. Department of Health and Human (US DHHS). 2015. U.S. Public Health Service recommendation for fluoride concentration in drinking water for the prevention of dental caries. Public Health Rep. 130(4):318–331. 10.1177/003335491513000408 26346489
U.S. Environmental Protection Agency (US EPA). 1988. Recommendations for and Documentation of Biological Values for Use in Risk Assessment Washington D.C.: U.S. Environmental Protection Agency, Office of Research and Development, Office of Health and Environmental Assessment, Environmental Criteria and Assessment Office EPA/600/6-87/008 (NTIS PB88179874). https://cfpub.epa.gov/ncea/risk/recordisplay.cfm?deid=34855.
U.S. Environmental Protection Agency (US EPA). 1994. Methods for derivation of inhalation reference concentrations (RfCs) and application of inhalation dosimetry. Washington, DC: U.S. Environmental Protection Agency, Office of Research and Development, Office of Health and Environmental Assessment, Environmental Criteria and Assessment Office. EPA/600/8-90/066F. https://cfpub.epa.gov/ncea/risk/recordisplay.cfm?deid=71993.
U.S. Environmental Protection Agency (US EPA). 2010a. Fluoride: Dose-response analysis for non-cancer effects. Washington: Office of Water, Health and Ecological Criteria Division. 820-R-10-018. https://www.epa.gov/sites/production/files/2015-09/documents/fluoride-study-summaries.pdf.
U.S. Environmental Protection Agency (US EPA). 2010b. Fluoride: Exposure and relative source contribution analysis. Washington D.C.: Office of Water, Health, and Ecological Criteria Division. 820-R-10-015. https://www.epa.gov/dwstandardsregulations/fluoride-risk-assessment-and-relative-source-contribution.
U.S. Environmental Protection Agency (US EPA). 2013. Basic information about fluoride in drinking water: Review of fluoride drinking water standard. https://www.epa.gov/dwsixyearreview/review-fluoride-drinking-water-regulation.
Vesterinen HM Sena ES Egan KJ Hirst TC Churolov L Currie GL Antonic A Howells DW Macleod MR 2014. Meta-analysis of data from animal studies: a practical guide. J Neurosci Methods. 221:92–102. 10.1016/j.jneumeth.2013.09.010 24099992
Vishnevskii VL EL Nichnykh LN 1969. A toxicological and morphological characterization of the action of different concentrations of inhaled hydrogen fluoride on the body. Tr Tsentr Nauchno-Issled Proektn-Konstr In. 2:143–147.
Vorhees CV Williams MT 2006. Morris water maze: procedures for assessing spatial and related forms of learning and memory. Nat Protoc. 1(2):848–858. 10.1038/nprot.2006.116 17406317
Vorhees CV Williams MT 2014. Assessing spatial learning and memory in rodents. ILAR J. 55(2):310–332. 10.1093/ilar/ilu013 25225309
Wang G, Li J, Zhu H, Zhu J. 2006. Effect of different doses of chronic exposure of fluoride on rat learning and memory behavior. Studies of Trace Elements and Health. 23(2):1-2.
Wang J Ge Y Ning H Wang S 2004. Effects of high fluoride and low iodine on biochemical indexes of the brain and learning-memory of offspring rats. Fluoride. 37(3):201–208.
Waterhouse C Taves D Munzer A 1980. Serum inorganic fluoride: changes related to previous fluoride intake, renal function and bone resorption. Clin Sci (Lond). 58(2):145–152. 10.1042/cs0580145 7357834
Wei N Dong Y Wang Y Guan Z 2014. Effects of chronic fluorosis on neurobehavioral development in offspring of rats and antagonistic effect of vitamin E. Chinese Journal of Endemiology. 33(2):125–128.
Whitford GM 1996. The Metabolism and Toxicity of Fluoride. Monographs in Oral Science. 2nd ed. New York: Karger Publishers; p. I–XIII.
Whitford GM Pashley DH 1984. Fluoride absorption: the influence of gastric acidity. Calcif Tissue Int. 36(3):302–307. 10.1007/BF02405334 6088010
Whitford GM Whitford JL Hobbs SH 2009. Appetitive-based learning in rats: lack of effect of chronic exposure to fluoride. Neurotoxicol Teratol. 31(4):210–215. 10.1016/j.ntt.2009.02.003 19236913
World Health Organization (WHO). 1994. Fluorides and oral health. Report of a WHO Expert Committee on Oral Health Status and Fluoride Use. Geneva, Switzerland: WHO (World Health Organization). 846. https://apps.who.int/iris/bitstream/10665/39746/1/WHO_TRS_846.pdf
Wu C Gu X Ge Y Zhang J Wang J 2006. Effects of high fluoride and arsenic on brain biochemical indexes and learning-memory in rats. Fluoride. 39(4):274–279.
Wu N Zhao Z Gao W Li X 2008. Behavioral teratology in rats exposed to fluoride. Fluoride. 41(2):129–133.
Xu X Zhang Z Shen X 2001. The influence of fluorosis on learning-memory behaviors of mice and the activities of SOD and the content of MDA in the brain. China Public Health. 17(1):8–10.
Zhang C Ren C Chen H Geng R Fan H Zhao H Guo K Geng D 2013. The analog of Ginkgo biloba extract 761 is a protective factor of cognitive impairment induced by chronic fluorosis. Biol Trace Elem Res. 153(1-3):229–236. 10.1007/s12011-013-9645-4 23605048
Zhang J Zhu W Zhang Z 2009. The effect of fluorine exposure of pregnant rats on the learning and memory capabilities of baby rats (Influence of fluorosis on learning memory of pup rats and activities of SOD and content of MDA in brain). Chin J Publ Health. 25:1347–1348.
Zhang Z, Shen X, Xu X. 2001. Effects of selenium on the damage of learning-memory ability of mice induced by fluoride. Wei sheng yan jiu. 30(3):144-146.
Zhang Z Sun Y Zheng X 2015. The synaptic mechanism of learning-memory injury induced by chronic fluorosis in brain. Journal of Zhejiang Normal University: Natural Sciences. 38(1):1–8.
Zhang Z, Xu X, Shen X. 1999. Effect of fluoride exposure on synaptic structure of brain areas related to learning-memory in mice. Wei sheng yan jiu. 28(4):210-212.
Zhu Y-l, Zheng Y-j, LV XM, Ma Y, Zhang J. 2012. Effects of fluoride exposure on performance in water labyrinth and monoamine neurotransmitters of rats. Journal of Xinjiang Medical University. 3:014.