# Discussion

## Summary

Results show low-to-moderate level-of-evidence in developmental and adult exposure studies for a pattern of findings suggestive of an effect on learning and memory (Table 10). Level-of-evidence conclusions were rated down due to concern for indirectness and risk of bias. The evidence was strongest for adult exposure studies using the Morris water maze. The evidence is strongest (moderate level-of-evidence) in animals exposed as adults tested in the Morris water maze and weaker (low level-of-evidence) in animals exposed during development.

In many cases, across the entire dose range tested, whether the effects were specifically related to learning and memory—versus a possible impact on motor or sensory function that could have impaired the ability of the animal to perform the learning and memory tests as measured—was not possible to discern. Also unclear is the extent to which skeletal fluorosis might have occurred, especially at the highest concentrations tested. Although skeletal fluorosis is associated most often with chronic durations of exposure and longer durations than those used in the neurobehavioral literature. Additional studies are required to achieve higher confidence in the specificity of the responses as learning or memory impairments and in quantitative measures such as effect sizes, points of departure, identification of NOEL or LOEL doses, or parameters for benchmark dose analysis. Based on control values (means and SD/SEs) and the number of animals per group, the studies appear statistically underpowered to detect <10% or <20% change from controls for most behavioral endpoints.

## Relevance to Human Exposure Levels

Very few studies assessed learning and memory effects at exposure levels near 0.7 parts per million, the recommended level for community water fluoridation in the United States. No effects were observed at the lowest concentration tested of 0.9 ppm (0.23 mg/kg-d) in adult male BALB/c mice treated with for 30 days (Liu et al. 2014). No effects were observed at this concentration in learning and memory tests (Morris water maze, novel object recognition) or in tests of motor activity, depression, or anxiety. The lowest concentration tested in the included developmental studies was 11.3 ppm (1.63 mg/kg-d) (Jiang et al. 2014a).

Several adult exposure studies, most of which were published after the 2006 NRC review of 2–4 ppm,^13^ reported effects at 2.26 ppm (0.33–0.59 mg/kg-d, depending on the study), including impaired performance in the Morris water maze (Dong et al. 2015c; Liu et al. 2014; Liu et al. 2011; Liu et al. 2010; Liu et al. 2009), Y-maze (Xu et al. 2001; Zhang et al. 1999), and novel object recognition tests (Liu et al. 2014). Other studies tested this drinking water concentration but did not report statistically significant effects (Gao et al. 2009a; Gao et al. 2008a; Gao et al. 2008b; Zhu et al. 2012). Several of the Morris water maze studies using 2.26 ppm appear to be conducted by the same research group using a very similar experimental paradigm, finding effects at 2.26 ppm in some studies (Liu et al. 2011; Liu et al. 2010) but not in others (Gao et al. 2009a; Gao et al. 2008b). Some studies appear to combine reporting of the duplicate data with new results (Dong et al. 2015b; Dong et al. 2015c; Liu et al. 2011; Liu et al. 2010; Liu et al. 2009).

13 At levels below 4.0 mg/L, NRC found no evidence substantial enough to support negative health effects other than severe dental fluorosis (NRC 2006).

In the EPA exposure assessment of fluoride intake, the average drinking water concentration for public water systems at a 90% water consumption rate yielded an intake of 0.63–1.23 mg/d for children from 0.5 year to 14 years (US EPA 2010b). In the rodent literature, these daily water intakes were approximated in studies using drinking water concentrations of 7 to 9 ppm.^14^ The total oral intake of fluoride from all sources (drinking water and all other sources) was 1.2 to 2.41 mg/d for the same age groups. These total intakes were approximated by animal studies using drinking water concentrations of 9 to 29 ppm.

14 Using a rat body weight of 0.235 kg and, given that 90th percentile human intake is 0.63 mg/day for a 1-year-old and 1.23 mg/day for a 14-year-old, body weight-adjusted values would be as follows for a 1-year-old and a 14-year-old: 0.63 mg/day = 0.07 mg/kg-d for 1-year-old human (assumes body weight of 9 kg) and 1.23 mg/day = 0.021 mg/kg-d for 14-year-old human (assumes body weight of 60 kg). Assuming that the same health effects will occur in rats when the intake is adjusted using a BW^3/4^ allometric scaling, the following body weight-adjusted intakes for rats would be: 0.07 mg/kg-d × (9 kg / 0.235 kg)^3/4^ = 1.08 mg/kg-d and 0.021 mg/kg-d × (60 kg / 0.235 kg)^3/4^ = 1.31 mg/kg-d. In mg/day: 1.08 mg/kg-d × 0.235 kg = 0.25 mg/day and 1.31 mg/kg-d × 0.235 kg = 0.31 mg/day. Converting to ppm would give: 0.25 mg/day / 0.034 L/day = 7.4 mg/L = 7 ppm and 0.31 mg/day / 0.034 L/day = 9.1 mg/L = 9 ppm.

Assessing effects of fluoride at 0.7-ppm concentration in future studies will be difficult for various reasons. One is the background levels of fluoride in drinking water; the use of reverse osmosis filtration, however, might obviate this issue. When reported, detection level ranges in drinking water were 0.2–1.7 mg/L (Appendix V); the level of quantitation and the margin of error around those levels, however, typically were not reported. More important could be the level of fluoride in normal rodent food. Background levels in diet were less commonly reported, but included 10 ppm (Mullenix et al. 1995) and up to 25.57 mg/kg of diet (Hong et al. 2005).

Several studies in rodents cited in this document measured serum or plasma levels of fluoride following exposures to various elevated levels in drinking water (Appendix U). These studies reported fluoride concentrations in drinking water ranging from approximately 80–8000 times higher than were measured in plasma/serum. This variability is perhaps not surprising because many factors can affect the ratios for substances that are relatively rapidly cleared from blood, including (1) the time between removal from, or the last exposure, to drinking water—which is not reported in studies; (2) the age of the animal and its related capacity of mineralized tissues to take up circulating fluoride; and (3) potential inter strain and species differences in renal clearance rates.

Understanding the relationship between “applied dose,” as represented by drinking water concentration, and resulting blood levels is critical in extrapolating adverse health effects from rodent studies to humans. In this respect, the relationship between drinking water fluoride concentrations and resulting blood levels of fluoride in young healthy adult humans has been described as a numerical equivalence between drinking water concentrations expressed as mg/L, and blood concentrations expressed as µmoles/L, or approximately a factor of 1000 (NRC 1993).^15^ This value falls within the range of ratios cited above for rodent studies. Dunipace et al. (1995) and National Research Council (NRC 2006), however, postulated that the applied drinking water “dose” to rats to achieve a plasma level equivalent to humans would need to be fivefold higher. Given the myriad variables that could influence these measured relationships in both animal and human studies, assuming approximate equivalence is not unreasonable, nor is assuming that health effects related to drinking water concentrations can be directly compared in rodents and humans from the perspective of kinetics.

15 On page 56–57, the text was changed from “In this respect, the relationship between drinking water fluoride concentrations and resulting blood levels of fluoride in young healthy adult humans has been described as an equivalence between drinking water concentrations expressed as mg/L, and blood concentrations expressed as µg/L, or approximately a factor of 1000 (NRC 1993)” to “In this respect, the relationship between drinking water fluoride concentrations and resulting blood levels of fluoride in young healthy adult humans has been described as a numerical equivalence between drinking water concentrations expressed as mg/L, and blood concentrations expressed as µmoles/L, or approximately a factor of 1000 (NRC 1993).” [August 19, 2016].

## Limitations in the Literature Base

- Deficiencies in study design, performance, and reporting limited the utility of several studies. Of the 68 included studies, 19 were considered to have a very severe risk of bias. Duplicate publication of the same results also occurred.
- Methodology descriptions of the behavioral studies often omitted specific information on how behavioral tests were conducted, configuration of the test apparatus, and specifics on test apparatus specifications, for example, for Morris water maze, the relative size of tank and platform and specifications of visual cues; size of activity arena; configuration of avoidance apparatus.
- Information was lacking on alternative sources of fluoride, for example, food or water supply.
- Relatively few developmental studies have focused on levels of fluoride exposure below 25 ppm in drinking water (Table 6). Most of these studies have design issues including lack of reporting of randomization, blinding at outcome assessment, or lack of controlling for litter effects.
- The majority of the learning and memory studies, which indicated an effect of exposure, were maze or avoidance studies. Often, the outcome endpoint was a simple latency measurement in the final training session rather than an evaluation of the acquisition of the task (increase in performance over time) to demonstrate learning. Thus, interpretation of the data is hindered by inability to exclude alterations from baseline levels or differences in motor-related performance over the training session as contributing factors.

## Limitations of the Systematic Review

- Evidence synthesis was restricted to potential learning and memory effects of fluoride.
- Additional analyses could be conducted to understand patterns of findings between learning and memory and other behavioral responses, such as motor and sensory function, and general systematic toxicity.
- This review focused on selected behavioral measures. Studies examining fluoride exposure on endpoints assessing brain-related cellular, morphometric, or histological endpoints were considered beyond the scope of this analysis. Similarly, effects on thyroid function, which might alter specific neurobehavioral measures, were considered beyond the scope of this review. In the NRC report (NRC 2006), the histological, chemical, and molecular studies were considered to provide evidence that fluorides can interfere with the functions of the brain and the body by direct and indirect means. Potential mechanisms described included reduced brain content of lipids and phospholipids, phosphohydrolases and phospholipase D, and other proteins; inhibition of cholinesterase activity (including acetylcholinesterase); reduction in acetylcholine receptors in the brain; activation of Gp, a protein of the G family, which mediates the release of many central nervous system transmitters; and increased production of free radicals in the brain. Cellular effects of the neocortext, hippocampus, and amygdala also were described in rat studies.
- Dose levels were converted to fluoride equivalents (F) expressed as mg/kg-d and ppm (e.g., 100 ppm sodium fluoride = 45.3 ppm fluoride). Most studies reported sodium fluoride as the form of fluoride administered. In several studies, the specific form of the chemical administered to animals was reported simply as “fluoride” with no details on counter ion, source, or purity, and no conversions to ionic fluoride equivalents were made. Dose levels expressed in fluoride equivalents would overestimate dose levels if, in fact, sodium fluoride were the test compound administered.
- Values for dose conversion (i.e., body weight, food, and water consumption) were based on EPA dosimetry guides (US EPA 1988; 1994). The European Food Safety Authority has developed more recent guidance on default values (EFSA 2012). Use of different default values can influence the dose levels as expressed in mg/kg.
- A meta-analysis was not performed in the current review, but quantitative approaches could be one way to understand sources of heterogeneity more completely and how they might affect confidence ratings, that is, heterogeneity for dose level could lead to greater confidence in dose-response assessment, while heterogeneity due to risk of bias might lead to reduced confidence.
- The ability to address potential publication bias was limited due to (1) challenges of having to select one outcome per study using approaches such as funnel plots when multiple endpoints related to the primary outcome were reported; (2) three or fewer studies being available for certain behavior tests; and (3) a lack of reporting on funding and conflict of interest in papers. In addition, analytical tools, such as funnel plots or trim-and-fill approaches, could be useful to assess publication bias but also have substantial limitations and should be interpreted with caution (Guyatt et al. 2011c). These limitations are especially pertinent for studies having small sample sizes, as is the case in the fluoride literature. In the current analysis, publication bias was described as “undetected.” This determination is based on GRADE guidance to use ratings of either “undetected” or “strongly suspected,” acknowledging the difficulty in having confidence that publication bias is absent and identifying a threshold to rate down the quality of evidence based on its presence (Guyatt et al. 2011c).

## Data Gaps and Research Needs

Additional studies are required to have higher confidence in the specificity of the responses as learning or memory impairments and in quantitative measures such as effect sizes, points of departure, identification of NOEL or LOEL doses, or parameters for benchmark dose analysis. Future research should consider:

- Use of low doses that are more applicable to human exposure levels and include characterization of background levels of fluoride in drinking water and diet. Assessing effects of fluoride at 0.7-ppm concentration will be difficult, given analytical capabilities to quantify low concentrations of fluoride in drinking water and the diet. In addition, use and interpretation of results from studies that use low fluoride rodent diets is likely to be challenging because nutritional components might change as a function of methods to remove fluoride and thus, not adequately support rodent growth, development, and adult health.
- Assessment of potential confounding from effects on motor and sensory function.
- Characterization of differences in response associated with sex, lifestage at exposure, duration of exposure, species, and strain.
- Evaluation and replication of the reported neuropathology associated with exposure.
- Addressing of several common study design and reporting deficiencies in the included studies.
- In particular, additional studies should:
  - Employ a wider range of doses and be appropriately powered with adequate numbers of animals to detect small effect sizes.
  - Be attentive to randomization and blinding during the study and at outcome assessment.
  - Report purity and source of test compound.
  - Control for litter effects in developmental studies.
  - Use repeated measures statistics when appropriate, and perform separate analyses of males and females.

## Conclusion

Very few studies assessed learning and memory effects in experimental animals (rats and mice) at exposure levels near 0.7 parts per million, the recommended level for community water fluoridation in the United States. At concentrations higher than 0.7 parts per million, this systematic review found a low to moderate level-of-evidence that suggests adverse effects on learning and memory in animal exposed to fluoride. The evidence is strongest (moderate level-of-evidence) in animals exposed as adults and weaker (low level-of-evidence) in animals exposed during development. Confidence in these findings was reduced primarily based on potential confounding of the learning and memory assessments by deficits in motor function or fear and risk of bias limitations. Additional research is needed, in particular to address potential effects on learning and memory following exposure during development to fluoride at levels nearer to 0.7 parts per million. NTP is conducting laboratory studies in rodents to fill data gaps identified by this systematic review of the animal studies. The findings from those studies will be included in a future systematic review to evaluate potential neurobehavioral effects from exposure to fluoride during development with consideration of human, experimental animal and mechanistic data.