# Results

## Literature Search Results

The database searches yielded 4,643 unique records, and 13 records were identified from reviewing the reference list of included studies or the Fluoride Action Network.^7, 8 ^Of the 4,656 studies identified, 4,552 were excluded during title and abstract screening, 104 were reviewed at the full-text level, and 68 studies were considered relevant to the PECO statement and were included (Figure 3). Most included studies were published after 2000 (Figure 4). A list of excluded studies is available on the HAWC fluoride project (https://hawcproject.org/assessment/126/) site.

7 Thirteen studies were identified as potentially relevant during the reference search of included studies and the Fluoride Action Network website. Two of these were not considered relevant based on full-text review (Bai et al. 2010; Vishnevskii and EL Nichnykh 1969), and we were unable to obtain a full-text record for one (Zhang et al. 2015). Thus, 10 of the 13 records identified from other sources were included.

8 No relevant records were identified from the chemical toxicity databases after review of dossiers identified using the search term “fluoride.” USEPA HPV Challenge Program Robust Summaries and Test Plans: The submission package for “Fatty Nitrogen Derived Amines Category” was reviewed for relevance. European Chemicals Agency (ECHA) Registration dossiers (“REACH”): Study summaries for repeated dose toxicity, reproduction, and developmental toxicity/teratogenicity were reviewed for sodium fluoride, potassium fluoride, calcium fluoride, ammonium fluoride, and magnesium sodium fluoride silicate.

Figure 3

Study Flow Selection Diagram

Figure 4

Publication Time Trend

Nineteen of the 68 studies (see Included Studies) were considered to pose a very serious overall risk of bias (Appendix C), primarily based on concern for at least 3 of the following factors: lack of randomization, lack of blinding at outcome assessment in conjunction with not using automated tools to collect information, lack of reporting on what was administered to animals (source, purity, chemical form of fluoride), lack of control for litter effects, lack of expected response in control animals, and lack of reporting of key study information such as the number of animals treated or sex. Across all the studies, information often was not reported and assumed not conducted, resulting in an assessment of “probably high” risk of bias. Authors were queried for missing information, and responses received were used to update risk of bias assessments. Sixteen of the 48 studies that reported findings related to learning and memory were excluded from the evidence synthesis due to concerns for serious risk of bias, which left 32 studies for use in the primary analysis.

### Included Studies

1. Balaji B, Kumar EP, Kumar A. 2015. Evaluation of standardized Bacopa monniera extract in sodium fluoride-induced behavioural, biochemical, and histopathological alterations in mice. Toxicol Ind Health. 31(1):18-30. http://dx.doi.org/10.1177/0748233712468018
2. Balayssac D, Richard D, Authier N, Nicolay A, Jourdan D, Eschalier A, Coudoré F. 2002. Absence of painful neuropathy after chronic oral fluoride intake in Sprague–Dawley and Lou/C rats. Neurosci Lett. 327(3):169-172. http://dx.doi.org/10.1016/S0304-3940(02)00421-4
3. Banji D, Banji OJ, Pratusha NG, Annamalai A. 2013. Investigation on the role of Spirulina platensis in ameliorating behavioural changes, thyroid dysfunction and oxidative stress in offspring of pregnant rats exposed to fluoride. Food Chem. 140(1-2):321-331. http://dx.doi.org/10.1016/j.foodchem.2013.02.076
4. Baran-Poesina V, Negres S, Dobrescu D, Dimcevici-Poesina N, Dimcevici-Poesina A, Feghiu A, Soare T, Militaru M. 2013. Experimental pharmacological researches regarding the influence of sodium fluoride in allopathic and homeopathic doses on central nervous system's performances. A correlation between behavioral response in classic maze test and morphological aspects of cerebral cortex. Farmacia. 61(4):781-799.
5. Bartos M, Gumilar F, Bras C, Gallegos CE, Giannuzzi L, Cancela LM, Minetti A. 2015. Neurobehavioural effects of exposure to fluoride in the earliest stages of rat development. Physiol Behav. 147:205-212. http://dx.doi.org/10.1016/j.physbeh.2015.04.044
6. Basha PM, Rai P, Begum S. 2011. Fluoride toxicity and status of serum thyroid hormones, brain histopathology, and learning memory in rats: a multigenerational assessment. Biol Trace Elem Res. 144(1-3):1083-1094. http://dx.doi.org/10.1007/s12011-011-9137-3
7. Basha PM, Sujitha N. 2012. Combined impact of exercise and temperature in learning and memory performance of fluoride toxicated rats. Biol Trace Elem Res. 150(1-3):306-313. http://dx.doi.org/10.1007/s12011-012-9489-3
8. Bataineh HN, Nusier MK. 2006. Impact of 12-week ingestion of sodium fluoride on aggression, sexual behavior, and fertility in adult male rats. Fluoride. 39(4):293-301.
9. Bera I, Sabatini R, Auteri P, Flace P, Sisto G, Montagnani M, Potenza MA, Marasciulo FL, Carratu MR, Coluccia A et al. 2007. Neurofunctional effects of developmental sodium fluoride exposure in rats. Eur Rev Med Pharmacol Sci. 11(4):211-224.
10. Bhatnagar M, Rao P, Jain S, Bhatnagar R. 2002. Neurotoxicity of fluoride: neurodegeneration in hippocampus of female mice. Indian J Exp Biol. 40(5):546-554.
11. [Chen H, Geng D. 2011. The change of cognition induced by chronic fluoride in rats. Acta Academiae Medicinae Xuzhou 31(5):319-322.]*
12. Chioca LR, Raupp IM, Da Cunha C, Losso EM, Andreatini R. 2008. Subchronic fluoride intake induces impairment in habituation and active avoidance tasks in rats. Eur J Pharmacol. 579(1-3):196-201. http://dx.doi.org/10.1016/j.ejphar.2007.10.019
13. [Dong Y-T, Wang Y, Wei N, Guan Z-Z. 2015. Expression levels of brain muscarinic acetylcholine receptor in offspring rats of drinking-water borne fluorosis. Chinese Journal of Endemiology. 34(5):326-330.]
14. [Dong Y-T, Wang Y, Wei N, Guan Z-Z. 2015. Expression of muscarinic acetylcholine receptors in the brain of rats with chronic fluorosis. Chinese Journal of Endemiology. 34(2):84-88.]
15. Dong Y-T, Wang Y, Wei N, Zhang Q-F, Guan Z-Z. 2015. Deficit in learning and memory of rats with chronic fluorosis correlates with the decreased expressions of M1 and M3 muscarinic acetylcholine receptors. Arch Toxicol. 89(11):1981-1991. http://dx.doi.org/10.1007/s00204-014-1408-2
16. Ekambaram P, Paul V. 2001. Calcium preventing locomotor behavioral and dental toxicities of fluoride by decreasing serum fluoride level in rats. Environ Toxicol Pharmacol. 9(4):141-146. http://dx.doi.org/10.1016/S1382-6689(00)00063-6
17. Ekambaram P, Paul V. 2002. Modulation of fluoride toxicity in rats by calcium carbonate and by withdrawal of fluoride exposure. Pharmacol Toxicol. 90(2):53-58. http://dx.doi.org/10.1034/j.1600-0773.2002.900201.x
18. Ekambaram P, Paul V. 2003. Effect of vitamin D on chronic behavioral and dental toxicities of sodium fluoride in rats. Fluoride. 36(3):189-197.
19. El-lethey H, Kamel M, Shaheed I. 2011. Perinatal exposure to sodium fluoride with emphasis on territorial aggression, sexual behaviour and fertility in male rats. Life Science Journal-Acta Zhengzhou University Overseas Edition 8(2):686-694.
20. El-lethey HS, Kamel MM. 2011. Effects of black tea in mitigation of sodium fluoride potency to suppress motor activity and coordination in laboratory rats. J Am Sci. 7:243-254.*
21. El-lethey HS, Kamel MM, Shaheed IB. 2010. Neurobehavioral toxicity produced by sodium fluoride in drinking water of laboratory rats. J Am Sci. 6(5):54-63.*
22. El-lethey HS, Shaheed IB. 2011. Potential health impact of black tea against Na-F-Induced alterations in territorial aggression, sexual behaviour and fertility of male rats. Life Sci J. 8:828-839.
23. Elliott L. 1967. Lack of effect of administration of fluoride on the central nervous system of rats. Acta Pharmacol Toxicol (Copenh) 25(3):323-328. http://dx.doi.org/10.1111/j.1600-0773.1967.tb01439.x
24. Flace P, Benagiano V, Vermesan D, Sabatini R, Inchingolo A, Auteri P, Ambrosi G, Tarullo A, Cagiano R. 2010. Effects of developmental fluoride exposure on rat ultrasonic vocalization, acoustic startle reflex and pre-pulse inhibition. Eur Rev Med Pharmacol Sci. 14(6):507-512.
25. [Gao Q, Liu YJ, Guan ZZ, Wu CX, Long YG. 2008. Level of oxidative stress in rat brains and learning and memory function of rats with chronic fluorosis. Chinese Journal of Endemiology. 27(4):371-373.]
26. [Gao Q, Liu YJ, Wu CX, Long YG, Guan ZZ. 2008. Effects of fluoride on learning and memory and cholinesterase activity in rat brains. Chinese J Endemiology. 27(2):128-130.]
27. Gao Q, Liu Y-J, Guan Z-Z. 2009. Decreased learning and memory ability in rats with fluorosis: increased oxidative stress and reduced cholinesterase activity in the brain. Fluoride. 42(4):277-285.
28. [Gao YL, Liu L, Young L, Huan LZ, Jin HH. 2009. Effects of learning and memory of fluoride and the antagonism of selenium in rats. Studies of Trace Elements and Health. 26:1-3.]*
29. Gopal K, Saxena R, Gupta G, Rana M, Agrawal D. 2006. Fluoride induced alterations in neurobehavioural and cardiovascular responses in rats. J Advanced Zool 27(1):1-7.
30. Gui C-Z, Ran L-Y, Li J-P, Guan Z-Z. 2010. Changes of learning and memory ability and brain nicotinic receptors of rat offspring with coal burning fluorosis. Neurotoxicol Teratol. 32(5):536-541. http://dx.doi.org/10.1016/j.ntt.2010.03.010
31. Han H, Du W, Zhou B, Zhang W, Xu G, Niu R, Sun Z. 2014. Effects of chronic fluoride exposure on object recognition memory and mRNA expression of SNARE complex in hippocampus of male mice. Biol Trace Elem Res. 158(1):58-64. http://dx.doi.org/10.1007/s12011-014-9889-7
32. [Hong JH, Ge YM, H.M. N. 2005. Effects of High Fluoride and Low Iodine on Learning-Memory and TchE of Brain in Offspring Rats. China Preventive Medicine. 6:489-491.]*
33. Jain A, Mehta VK, Chittora R, Mahdi AA, Bhatnagar M. 2015. Melatonin ameliorates fluoride induced neurotoxicity in young rats: An In Vivo evidence. Asian Journal of Pharmaceutical and Clinical Research. 8(4):164-167.
34. Jetti R, Raghuveer C, Rao C. 2016. Protective effect of ascorbic acid and Ginkgo biloba against learning and memory deficits caused by fluoride. Toxicol Ind Health. 32(1):183-187. http://dx.doi.org/10.1177/0748233713498460
35. Jiang C, Zhang S, Liu H, Guan Z, Zeng Q, Zhang C, Lei R, Xia T, Wang Z, Yang L. 2014. Low glucose utilization and neurodegenerative changes caused by sodium fluoride exposure in rat’s developmental brain. Neuromolecular Med. 16(1):94-105. http://dx.doi.org/10.1007/s12017-013-8260-z
36. Jiang S, Su J, Yao S, Zhang Y, Cao F, Wang F, Wang H, Li J, Xi S. 2014. Fluoride and arsenic exposure impairs learning and memory and decreases mGluR5 expression in the hippocampus and cortex in rats. PloS one. 9(4):e96041. http://dx.doi.org/10.1371/journal.pone.0096041
37. Kivrak Y. 2012. Effects of fluoride on anxiety and depression in mice. Fluoride. 45(3):302-306.
38. Li M, Cui J, Gao Y, Zhang W, Sun L, Liu X, Liu Y, Sun D. 2015. Pathological changes and effect on the learning and memory ability in rats exposed to fluoride and aluminum. Toxicol Res. 4(5):1366-1373. http://dx.doi.org/10.1039/C5TX00050E
39. Liu F, Ma J, Zhang H, Liu P, Liu Y-P, Xing B, Dang Y-H. 2014. Fluoride exposure during development affects both cognition and emotion in mice. Physiol Behav. 124:1-7.
40. [Liu WX. 1989. Experimental study of behavior and cerebral morphology of rat pups generated by fluorotic female rat. Zhonghua Bing Li Xue Za Zhi 18(4):290-292.]
41. [Liu YJ, Gao Q, Long YG, Yu YN, Guan ZZ. 2011. Influence of chronic fluorosis on expression of phospho-Elk-1 in rat brains. Chinese Journal of Endemiology. 30(3):251-255.]
42. [Liu YJ, Gao Q, Wu CX, Long YG, Guan ZZ. 2009. Modified expression of extracellular signal-regulated protein kinase signal transduction in rat brains and changed capacity of learning and memory of rats with chronic fluorosis. Chinese J Endemiology. 28(1):32-35.]
43. Liu Y-J, Gao Q, Wu C-X, Guan Z-Z. 2010. Alterations of nAChRs and ERK1/2 in the brains of rats with chronic fluorosis and their connections with the decreased capacity of learning and memory. Toxicol Lett. 192(3):324-329. http://dx.doi.org/10.1016/j.toxlet.2009.11.002
44. Ma J, Liu F, Liu P, Dong Y-Y, Chu Z, Hou T-Z, Dang Y-H. 2015. Impact of early developmental fluoride exposure on the peripheral pain sensitivity in mice. International Journal of Developmental Neuroscience: the official journal of the International Society for Developmental Neuroscience. 47(Part B):165-171. http://dx.doi.org/10.1016/j.ijdevneu.2015.09.005
45. Mullenix PJ, Denbesten PK, Schunior A, Kernan WJ. 1995. Neurotoxicity of sodium fluoride in rats. Neurotoxicol Teratol. 17(2):169-177. http://dx.doi.org/10.1016/0892-0362(94)00070-T
46. Niu R, Liu S, Wang J, Zhang J, Sun Z, Wang J. 2014. Proteomic analysis of hippocampus in offspring male mice exposed to fluoride and lead. Biol Trace Elem Res. 162(1-3):227-233. http://dx.doi.org/10.1007/s12011-014-0117-2
47. Niu R, Sun Z, Cheng Z, Li Z, Wang J. 2009. Decreased learning ability and low hippocampus glutamate in offspring rats exposed to fluoride and lead. Environ Toxicol Pharmacol. 28(2):254-258. http://dx.doi.org/10.1016/j.etap.2009.04.012
48. Niu R, Sun Z, Wang J, Cheng Z, Wang J. 2008. Effects of fluoride and lead on locomotor behavior and expression of Nissl body in brain of adult rats. Fluoride. 41(4):276-282.
49. Paul V, Ekambaram P, Jayakumar A. 1998. Effects of sodium fluoride on locomotor behavior and a few biochemical parameters in rats. Environ Toxicol Pharmacol. 6(3):187-191. http://dx.doi.org/10.1016/S1382-6689(98)00033-7
50. Pereira M, Dombrowski PA, Losso EM, Chioca LR, Da Cunha C, Andreatini R. 2011. Memory impairment induced by sodium fluoride is associated with changes in brain monoamine levels. Neurotox Res. 19(1):55-62. http://dx.doi.org/10.1007/s12640-009-9139-5
51. Raghu J, Raghuveer VC, Rao MC, Somayaji NS, Babu PB. 2013. The ameliorative effect of ascorbic acid and Ginkgo biloba on learning and memory deficits associated with fluoride exposure. Interdiscip Toxicol. 6(4):217-221. http://dx.doi.org/10.2478/intox-2013-0032
52. Reddy MM, Karnati PR. 2015. Protective effects of aqueous extract of fruit pulp of Tamarindus indica on motor activity and metabolism of the gastrocnemius muscle of rats treated with fluoride. International Journal of Toxicological and Pharmacological Research. 7(5):241-246.
53. [Rumiantsev G, Novikov S, Mel'nikova N, Levchenko N, Kozeeva E. 1988. Experimental study of the biological effect of salts of hydrofluosilicic acid. Gigiena i sanitariia. (11):80-82.]
54. Sarkozi K, Horvath E, Vezer T, Papp A, Paulik E. 2015. Behavioral and general effects of subacute oral arsenic exposure in rats with and without fluoride. Int J Environ Health Res. 25(4):418-431. http://dx.doi.org/10.1080/09603123.2014.958138
55. [Shen X, Zhang Z, Xu X. 2004. Effect of iodine and selenium on learning memory impairment induced by fluorosis and blood biochemical criterion of rats. Occupation and Health. 20:6-8.]*
56. Sun ZR, Liu FZ, Wu LN, Lu Y, Yu DK. 2008. Effects of high fluoride drinking water on the cerebral function of mice. Fluoride. 41(2):148-151.
57. [Wang G, Li J, Zhu H, Zhu. 2006. Effect of different doses of chronic exposure of fluoride on rat learning and memory behavior Studies of Trace Elements and Health 23:1-2.]*
58. Wang J, Ge Y, Ning H, Wang S. 2004. Effects of high fluoride and low iodine on biochemical indexes of the brain and learning-memory of offspring rats. Fluoride. 37(3):201-208.
59. [Wei N, Dong Y, Wang Y, Guan Z. 2014. Effects of chronic fluorosis on neurobehavioral development in offspring of rats and antagonistic effect of Vitamin E. Chinese Journal of Endemiology. 33(2):125-128.]
60. Whitford GM, Whitford JL, Hobbs SH. 2009. Appetitive-based learning in rats: lack of effect of chronic exposure to fluoride. Neurotoxicol Teratol. 31(4):210-215. http://dx.doi.org/10.1016/j.ntt.2009.02.003
61. Wu C, Gu X, Ge Y, Zhang J, Wang J. 2006. Effects of high fluoride and arsenic on brain biochemical indexes and learning-memory in rats. Fluoride. 39(4):274-279.
62. Wu NP, Zhao ZL, Gao W, Li XQ. 2008. Behavioral teratology in rats exposed to fluoride. Fluoride. 41(2):129-133.
63. [Xu X, Shen X. 2001. Effect of fluorosis on mice learning and memory behaviors and brain SOD activity and MDA content. China Public Health 17:8-10.]*
64. Zhang C, Ren C, Chen H, Geng R, Fan H, Zhao H, Guo K, Geng D. 2013. The analog of Ginkgo biloba extract 761 is a protective factor of cognitive impairment induced by chronic fluorosis. Biol Trace Elem Res. 153(1-3):229-236.
65. [Zhang J, Zhang Z. 2009. The effect of fluorine exposure of pregnant rats on the learning and memory capabilities of baby rats Chinese Journal of Public Health 25:1347-1348.]*
66. [Zhang Z, Shen X, Xu X. 2001. Effects of selenium on the damage of learning-memory ability of mice induced by fluoride. Wei Sheng Yan Jiu. 30(3):144-146.]
67. [Zhang Z, Xu X, Shen X. 1999. Effect of fluoride exposure on synaptic structure of brain areas related to learning-memory in mice. Wei Sheng Yan Jiu. 28(4):210-212.]
68. [Zhu YL, Zheng YJ, Ma Y, Zhang J. 2012. Effects of fluoride exposure on performance in water labyrinth and monoamine neurotransmitters of rats. Journal of Xinjiang Medical University. 35.]*

*Identified from other sources, [ ] non-English.

## Overview of Included Studies

A survey of included studies describing species, lifestage at exposure, and dose levels tested is presented in Table 6. Eighteen of the 68 studies (26%) were in non-English, defined as those for which a publicly available version in English was not available.^9^ English-translated versions of several studies were available in the publication Fluoride and are not classified as non-English.

9 (Chen and Geng 2011; Dong et al. 2015a; Dong et al. 2015b; Gao et al. 2008a; Gao et al. 2008b; Gao et al. 2009b; Hong et al. 2005; Liu 1989; Liu et al. 2011; Liu et al. 2009; Rumiantsev et al. 1988; Shen et al. 2004; Wang et al. 2006; Wei et al. 2014; Xu et al. 2001; Zhang et al. 2009; Zhang et al. 2001; Zhu et al. 2012).

Table 6 Description of Relevant Studies

Descriptor | Learning and Memory | Motor and Sensory Function | Depression | Anxiety | Other^1^
Number of Studies | 48 | 32 | 3 | 4 | 10
Non-English | 17 (35%) | 6 (19%) | 0 (0%) | 0 (0%) | 0 (0%)
Species
Rats | 39 | 24 | 0 | 2 | 8
Mice | 9 | 8 | 3 | 2 | 2
Lifestage of Exposure^2^
Adult | 33 | 22 | 3 | 2 | 5
Developmental | 16 | 11 | 0 | 2 | 5
Doses Range Tested^2^ | 0.45–271 ppm | 0.9–226 ppm | 0.9–90 ppm | 0.9–90 ppm | 1–136 ppm
Developmental | 1–200 ppm (n = 16)^3^ | 1–68 ppm (n = 11) | – | 2.26–61 ppm (n = 2) | 1–45 ppm (n = 5)
≤5 ppm | 2 studies | 3 studies | – | 1 study | 2 studies
≤4 ppm | 2 studies | 3 studies | – | 1 study | 2 studies
Adult | 0.45–271 ppm (n = 33) | 0.9–226 ppm (n = 22) | 0.9–90 ppm (n = 3) | 0.9–90 ppm (n = 2) | 40–136 ppm (n = 5)
≤5 ppm | 12 studies | 2 studies | 1 study | 1 study | 0 studies
≤4 ppm | 12 studies | 2 studies | 1 study | 1 study | 0 studies
Studies with Very Serious Risk of Bias^4^
Total | 16/48 | 9/32 | 0 | 0 | 3/10
Developmental | 9/16 | 5/11 | – | 0 | 2/5
≤5 ppm | 2/2 (100%) | 2/3 (66%) | – | – | –
≤4 ppm | 2/2 (100%) | 2/3 (66%) | – | – | –
Adult | 7/33 | 4/22 | 0 | 0 | 1/5
≤5 ppm | 2/12 (17%) | 0 | 0 | 0 | 0
≤4 ppm | 2/12 (17%) | 0 | 0 | 0 | 0
Studies Used for Evidence Synthesis
Total | 32 | – | – | – | –
Developmental | 7 (11–50 ppm) | – | – | – | –
≤5 ppm | 0 | – | – | – | –
≤4 ppm | 0 | – | – | – | –
Adult | 26 (0.45–226 ppm) | – | – | – | –
≤5 ppm | 10 | – | – | – | –
≤4 ppm | 10 | – | – | – | –

^1^ Other includes studies assessing grooming/urination/defecation; sexual behavior, territorial aggression, vocalization.

^2^ Expressed in ppm fluoride equivalents. The number of studies might not total because studies often tested multiple dose levels and some studies evaluated effects in multiple lifestages of exposure.

^3^ Duplicate data from Dong et al. (2015c) appear to be reported in a second study from this group Dong et al. (2015a).

^4^ See Appendix C.

### Behavioral Tests for Learning and Memory

Theories of learning stress the significance of drives and incentives or motivating factors in the process of acquisition and in establishing a memory of a task. In animal experimentation, there are a variety of motivating factors, including such incentives as escape from punishment, escape from water, satisfaction of hunger, satisfaction for novel experiences, sexual satisfaction, satisfaction of maternal drive, and satisfaction to return to home cage and cage mates. A relative efficacy exists for different degrees of reward and the degree-of-reward-value inherent in any incentive can be modified by varying the physiological condition of the animal (e.g., periods of deprivation).

All learning paradigms that rely on appetitive reinforcement (food or water) require animals to be placed on deprivation to increase reinforcement value. Once animals have learned to perform the task, with continued training to examine full acquisition or to transition to a more complicated paradigm, body weight is normally maintained at 80–85% of free feeding body weight. Although initially this condition might be stressful to the animals, the restricted caloric intake can be of health benefit. For toxicological assessments, consideration is required with regard to the initial health of the animals and the motivational incentive value of the appetitive reward. The use of aversive stimuli, which for the animal is reinforced by removing itself from experiencing, is by its nature stressful in the initial acquisition phase. The reinforcement value of the stimuli is a variable that requires consideration. For example, altering the pain threshold (diminished or elevated) will influence reinforcement value of a painful stimulus and, thus, acquisition.

The reliance on a motor response can result in issues that require consideration for interpretation. As an example, if latency is an outcome endpoint, absence of general motor performance equivalency could become an issue for concern. In maze-based tasks, latency often determines performance. In these cases, altered motor function or activity levels can significantly influence the outcome endpoint yet not reflect differences in learning. In avoidance tasks, for animals that display lower activity levels, performance on passive avoidance tasks can appear improved while animals with a higher level of activity can give the impression of poor performance, neither of which would directly reflect learning capability. The reverse is true for active avoidance paradigms.

Animals can display differences in response characteristic or level. For example, an animal might respond to the negative stimuli by freezing rather than escaping or might find an alternative method to endure the stimuli. These differences in response do not necessarily mean the animal has not learned the associations between cues—just that it is not performing as the test paradigm dictates. In various tests for learning and memory, the assessment of memory might inadvertently impose an extinction trial that would weaken the conditioned association between cues and influence any subsequent test session. As in all learning assessments, an understanding is required of the learning process and the manifestation of a learned behavior in an individual animal that differs from the defined response of the paradigm.

The following examples of test paradigms used to assess learning and memory in rodents are not intended to be inclusive. Rather, they reflect the tests represented in the literature for evaluating the effects of fluoride exposure on learning and memory.

#### Morris Water Maze

The Morris water maze is a standardized test used to evaluate aspects of spatial learning and memory in rats and mice (Vorhees and Williams 2006; 2014). The general paradigm is to allow the animal to navigate a circular water-filled tank to find a hidden platform that will allow for escape from the water. The animal accomplishes this task by using various visual cues within the spatial environment. The animal is allowed to search the tank for a defined period (60–120 seconds) to find the platform. Several sequential training trials are conducted (the most common is four trials per day). Several sequential daily training sessions are conducted consisting of multiple trials per day to reach a predetermined criterion of learning. Learning, as defined by acquisition of the task over training sessions, is evaluated by a decrease in the amount of time the animal takes to find the platform (latency), a decrease in the distance traveled to reach the platform, and (with video imaging techniques) a shift in the swimming pattern to achieve a more direct and efficient route to the platform. Additional measures collected include visual capability (seeing a visual platform above the water surface) and swimming speed across multiple sessions to confirm an absence of differences between groups that could affect performance on the Morris water maze and influence data interpretation regarding learning and memory. When the animal reaches a set criterion of performance for the Morris water maze (has learned the task), a spatial memory assessment (probe trial) is conducted. During this probe trial, the platform is removed and the search strategy of the animal is evaluated [time spent in escape platform quadrant (absolute and relative to each other quadrant), latency and distance traveled to the first time crossing the previous platform location, number of times the animal crosses the previous platform location]. These measures are collected across the total time interval for the probe trial (60–90 seconds) to capture the memory of the previous platform location (memory) and within equal time intervals (15-sec epochs) to capture the animal’s ability to detect the absence of the platform and to change the search strategy, respectively. To confirm a learning deficit, a “reversal-learning” session can follow the probe trial in which the animal is required to learn a new location of the escape platform. Motor strength, motor coordination, or attention can influence any isolated measures of latency or distance traveled, rather than acquisition (better performance over time), and thus, confound interpretation of change in learning. Many studies examining the effect of fluoride exposure on Morris water maze performance relied on such isolated measures, and the acquisition of the task was not analyzed. In addition, endpoints collected during the memory probe tests often were limited to motor-dependent tasks (e.g., latency to the initial find of the learned location of the previously hidden platform, number of times the animal swam across the platform site during a single trial). Few studies included an assessment of the time an animal spent in the “platform” location.

#### T-Maze

The T-maze is an apparatus shaped like the letter T that can be used to evaluate exploratory activity (in absence of a reinforcement) and, in a variety of ways, to evaluate learning and memory in experimental animals. Typically, a spontaneous alternation paradigm and a reinforced alternation paradigm (working memory) were used in the fluoride studies. Normal control animals (mice and rats) display a tendency to alternate their choice of an arm of the maze to enter (e.g., an entry into the right arm on trial 1 is highly likely to be followed by an entry into the left arm of the subsequent trial). In the absence of reinforcement, this behavior is termed spontaneous alteration. The normal alternating pattern is examined over trials in quick succession as a measure that the animal remembers the arm visited in the previous session. With reinforcement (positive or negative), the paradigm is termed a reinforced alternation paradigm. The animal is placed at the start location in the bottom of the T and allowed to traverse the alley of the maze, making a choice of turning right or left. One arm of the maze, which contains reinforcement, is considered the “correct” arm. The animal is removed from the maze and a subsequent trial conducted. Training consists of a defined number of trials within any one session and several sessions per day for a defined number of days, usually until the animals reach a previously defined criterion of the percentage of correct choices. The number of correct choices and latency to run the maze from the start location to the goal box is recorded. Acquisition is normally determined by a decrease in percentage of incorrect choices and a decrease in latency over time. Deficits in motor function can influence latency, and motivation level of the animal can influence latency and percentage of correct choices.

A multiple T-maze test is a complex maze having multiple T-junctions. Performance is measured as a right or wrong choice at each T intersection. Multiple T-mazes are used to address questions of place versus response learning and cognitive maps. A mouse or rat is placed in the maze and allowed to explore freely for a defined period across a few trials. Under food-deprivation conditions, the animal is placed in one T-end of the maze and allowed to explore the maze for a defined period to find the food reinforcement. This reinforced trial is repeated. Acquisition of the task is measured as a decrease in latency to obtain the reward and a decrease in percentage of incorrect choices at junctions. Motivation level and anxiety/fear level of the animal can influence latency and percentage of correct choices.

#### Y-Maze

The Y-maze is an apparatus with three arms, oriented at 120-degree angles from each other that can be used to assess exploratory behavior (animals tend to enter a less recently visited arm) or can be used, in conjunction with cued reinforcement, to examine learning and memory for selecting arm to enter. A Y-maze paradigm is similar to the T-maze paradigm in that it can record spontaneous alternation of arm entered or arms entered for reinforcement (positive or negative). A sequence of trials consists of placing the animal in the start location at the base of the maze and allowing the animal to traverse the length of the maze. Over trials, the sequence of choices is recorded to identify the pattern of alternation from one arm to the other. In controls, the choice sequence is expected to alternate with each trial under nonreinforced conditions (spontaneous alternation). For reinforced alternation, the animal’s entering a specific arm (either the same or different) is reinforced with each trial, depending on the test paradigm. Acquisition of the task is measured as a decrease in the number of choice errors (entering the incorrect arm). Latency from the start box to the goal box or to the choice point also can be recorded. Differences in motor function or motor performance can influence latency. Motivation level and anxiety/fear level of the animal can influence latency and percentage of correct choices.

#### Classic Maze

Classic maze performance is related to the animal’s progression over sessions to increase its performance as measured by latency or number of errors, depending on the maze design and paradigm. Although its design can vary, the classic maze generally requires the animal to learn to make a series of correct choices (turns) to navigate the maze successfully and receive reinforcement. Appetitive reinforcement, such as food reward, can be used with animals maintained at a level of restricted feeding to enhance motivation. Negative reinforcement also can be used. A standard paradigm for a classic maze involves the animal’s being placed in the start location of the maze and allowed to explore the maze freely for a defined period. A series of successive trials follows during which the animal learns to navigate the maze more quickly and correctly. Acquisition of the task is reflected as a decrease over trials in latency (time) to reach reinforcement or the number of times the animal makes an error in selecting the correct direction to take at a choice point, or both. Differences in motor function can influence latency. Motivation level of the animal and anxiety/fear level can influence latency and percentage of correct choices.

#### Passive Avoidance

Passive avoidance is a fear-motivated test used to evaluate associative learning and memory. An animal is required to learn to withhold a normal preferred response such as moving from a brightly illuminated large chamber into a smaller dark chamber or moving from an elevated platform to a lower floor. A standard paradigm involves the animal’s being placed in the nonpreferred side of the apparatus. The animal is allowed to explore the apparatus freely and, upon the first entry in the normally preferred side, a negative stimulus is delivered. The animal undergoes two or three training/test sessions. The strength of the learned association is indicated by an increase in latency to leave the “safe” chamber and enter the “non-safe” chamber over sessions. The strength of the association can be examined by eliminating the adverse stimuli and measuring the number of trials required for the animal to return to a pretraining latency to enter the “non-safe” side. The strength of the reinforcement (e.g., perception of pain from the shock) influences the strength of the learning. Motor activity level can influence latency, with a decreased activity level skewing the response to appear as if a greater level of learning occurred, while hyperactivity would cause the animal to move prematurely and thus, imply a deficit in learning.

#### Active Avoidance

Active avoidance is a fear-motivated test used to evaluate associative learning and memory. Animals learn to associate a conditioned stimulus (light, tone) with the delivery of an unconditioned negative stimulus (e.g., shock) and to move to a safe location to escape (escape response) or avoid (avoidance response) the negative stimulus. A standard paradigm involves the animal’s being placed in the test apparatus and allowed to explore the environment freely. A training trial is initiated by the delivery of a cue (light), followed within a defined time interval (5–10 sec as determined by the test parameters) by the presentation of a second cue (tone) paired with a shock (or other strong negative stimulus). The animal can escape the negative stimulus by moving from the “non-safe” environment upon the delivery of the first cue (avoidance) or with the second cue and shock (escape). With training, the animal learns an association between the cue (tone, conditioned stimulus) and the shock (unconditioned stimulus). Acquisition is demonstrated with an increase in avoidance responses and decrease in escape responses over the session. The number of escape losses (failing to make a response during the full shock delivery period), which is recorded, could reflect an absence of learned association between cue and shock or an increase in freezing behavior with fear. Active avoidance can be evaluated using various test paradigms, for example, one-way, with actively moving from one location to another; two-way, with actively moving back and forth between two locations with appropriate cues; and three-way, with the animal’s being allowed to choose between two locations to escape/avoid the stimuli such as occur in a Y-maze. As with any task requiring motor performance and latency, deficits in such ability can influence the outcome. With a fear-motivated test, the characteristics of the fear response can also influence the outcome of the test. Each factor can influence performance, independent of learning and memory as assessed by the testing paradigm.

#### Exploratory Behavior/Novelty Tests: Novel Object Recognition, Social Recognition, Social Novelty

These tests, which are based on an animal’s natural propensity toward novelty, evaluate an animal’s ability to recognize a previously presented stimulus or to adapt (habituate) to a novel environment. Stimuli can be an inanimate object, another animal (social recognition), or changes in the environment. When animals are exposed to a familiar object and a novel object, they frequently approach—and spend more time exploring—the novel object than the familiar object, which suggests the evidence of memory for the familiar object. In general, the paradigm consists of placing the test animal within a defined open arena and allowing it to adapt to the new environment. The animal is removed, and a novel object is placed within the arena. The animal is returned to the arena, and the number of contacts with the novel object and time spent within a defined radius of it are recorded. The animal is removed from the arena and a new object is placed into the arena in addition to the now familiar object. The proportion of time spent with each object and number of contacts are recorded over a defined period. As with any endpoint that relies on activity, deficits in motor function or activity level and exploration can influence the outcome in this paradigm. Although novel object recognition paradigms recently have been used with greater frequency in assessing the interactive nature of an animal with its environment, the range in differential preference between a familiar and a novel object is relatively narrow, seldom showing a preference above 70%. Thus, these results should be interpreted with caution. Differences in the approach to a novel object between rodent strains have been demonstrated that could influence test selection.

#### Operant Behavior

In this form of learning, the animal displays a behavior for which they receive reinforcement. Multiple test paradigms can be used for operant conditioning, and appetitive or aversive stimuli can be used to define the reinforcement paradigm. Operant conditioning offers additional power in the ability to elicit the behavior under a schedule of required performance (schedule-controlled behavior). This feature permits increasing complexity to evaluate the nature of a learning deficit. In a more standard experimental operant paradigm, animals are placed within an operant chamber containing a bar that can be pressed or an opening to nose poke to deliver a food pellet or fluid reward; the animals then are “shaped” to perform the operant task (bar press, nose poke) on a continuous reinforcement schedule during which every appropriate behavior results in reinforcement. Once the animal is trained on the continuous reinforcement schedule—has reached a defined level of performance—the paradigm can shift to a different schedule of reinforcement. This different schedule enables examination of the animal’s ability to learn a temporal association with behavior and reinforcement (interval) or an association of number of behavioral events and reinforcement (ratio), each of which can be set as fixed or variable. These then can increase in complexity or demand on the animal. Additional test paradigms and schedules can be used to test for other aspects of learning that are outside the focus of this document. Operant behavior offers a very powerful tool to assess learning capability and limitation; this test, however, is used rarely in assessments of neurotoxicity, given the demands of time and expertise and the equipment costs.

## Effects of Fluoride on Learning and Memory

### Evidence Synthesis

Results were analyzed two ways. First, the collection of studies for each general type of behavioral test (Morris water maze, Y-maze, etc.) was compiled. In many cases, the overall quality of the evidence for each type of behavior test clearly would warrant a downgrade based on serious concern for risk of bias. This concern arose because several individual studies were considered to have “probably high risk of bias” in several critical domains: randomization, blinding at outcome assessment (especially when computer-assisted or automated measurements were not made), exposure characterization, and control for litter effects in developmental studies (Appendix C). Thus, these studies were excluded when reaching level-of-evidence conclusions. Almost one third of the learning and memory studies were considered to present a very serious risk of bias. Nevertheless, the results of the excluded studies are summarized below and presented in Appendix D through Appendix J. An assessment on the impact of excluding these studies found that, if included, these studies would not have appreciably altered conclusions. Quality and level-of-evidence conclusions focused on learning and memory, although studies evaluating other aspects of behavior (motor and sensory function, depression, anxiety, grooming/urination/defecation, territorial aggression, and sexual behavior) were identified, data extracted, and assessed for risk of bias (see Appendix K through Appendix R).

No meta-analysis was conducted because few studies measured endpoints similarly in terms of study design, that is, use of same behavioral tests, dose levels, duration of exposure, lifestage at exposure, or species. Level-of-evidence conclusions were based on a narrative analysis of patterns of response across different testing paradigms and types of learning, including maze learning, avoidance learning, novel object recognition, and operant conditioning. The impact of potential confounding factors on the endpoint and subsequent interpretation also was considered. In many cases, the specificity of an effect as learning and memory could not be ascertained given the motor performance dependency of the tasks and the absence of data on motor or sensory functions to help interpret results from learning and memory tests. The extent to which skeletal fluorosis might have occurred is also unclear, especially at the higher concentrations tested; one would expect, however, that skeletal fluorosis more likely would be associated with exposure durations exceeding those that have been used in studies assessing neurobehavioral toxicity. Based on control values and the number of animals per group, most studies appear statistically underpowered to detect <10% or <20% change from controls for most behavioral endpoints.

Findings are summarized below with fluoride exposures expressed as ppm and as mg/kg-d format in Appendix S (individual studies) and Appendix T (range across studies for a given ppm level).

### Exposure during Development

A low level-of-evidence conclusion was reached based on a pattern of findings suggestive of an effect on learning and memory in rats or mice treated during gestation through postnatal day (PND) 28 or continuing until PND105 at dose levels of ~11 to 45.3 ppm fluoride (Dong et al. 2015c; El-lethey et al. 2010; Gui et al. 2010; Jiang et al. 2014a; Wang et al. 2004; Wei et al. 2014).^10^ The level-of-evidence was rated down due to concern for indirectness and lack of control for potential litter effects. Interpretation of behavioral data as a specific effect on learning and memory was hindered by concerns that the effects were secondary due to changes in motor or sensory function that could impair the animal’s ability to perform the task. This was considered a form of indirectness. Additional studies are required to have higher confidence in the specificity of the responses as learning or memory impairments and to provide quantitative measures such as the effect sizes, point of departure, identification of NOEL or LOEL doses, or parameters for benchmark dose analysis. No studies evaluated a male/female difference in response to fluoride treatment (male and female offspring were pooled during analysis) and studies used Sprague Dawley or Wistar rats, so discerning any sex or species differences in response was not possible. The group size ranged between 6 and 12 for the behavioral studies. Based on variability in the control groups, these group sizes were considered statistically underpowered to detect <10% or <20% change from controls for most behavioral endpoints. When reported, the fluoride concentrations in the drinking water of control groups ranged from 0.15 to 1.77 ppm (Dong et al. 2015c; Gui et al. 2010; Jiang et al. 2014b; Wei et al. 2014).

10 Duplicate data from (Dong et al. 2015b) appear to be reported in a second study from this group (Dong et al. 2015a).

#### Morris Water Maze

Several studies examined Morris water maze performance in animals exposed during development to ~11 to 50 ppm fluoride (Dong et al. 2015c; Gui et al. 2010; Jiang et al. 2014a; Wei et al. 2014). Exposed animals often took longer or traveled farther to find the platform during the acquisition phase (referred to as “escape time”) (Dong et al. 2015c; Gui et al. 2010; Jiang et al. 2014a) and magnitudes of the effects were often twice as great or more (Figure 5). Within a study, Morris water maze endpoints typically were internally consistent, that, if a slower escape time was observed at the end of the acquisition phase, the animals also displayed fewer platform crossings and spent less time in the target quadrant during the probe test. A NOEL was not identified, and the LOEL was 11.3 ppm fluoride in F1 generation Sprague Dawley male and female rats treated from gestation day (GD) 0 through PND60 (Jiang et al. 2014a). The one study that tested more than one dose level showed evidence for dose response (Jiang et al. 2014a). Some evidence was shown for dose response across studies, although variations in treatment time and endpoints assessed limited this analysis. Two studies were excluded based on concerns for overall high risk of bias (Wu et al. 2008; Zhang et al. 2009); (Appendix C). Across the remaining studies were “serious” concerns for risk of bias based on a lack of controlling for litter effects, which OHAT considered a critical risk of bias factor in developmental studies (see Figure 7). Failure to adjust for litter effects can exaggerate the statistical significance of experimental findings (Haseman et al. 2001). Also, in most of these studies, acquisition (learning) of the task either was not reported or limited to a latency measurement on the last day of training. This raised concerns for indirectness/confounding because assessment of learning and memory in the Morris water maze highly depends on latency and swimming capability. The longer latency during acquisition could reflect an effect on learning or, alternatively, impaired motor function.

Figure 5

Results from Developmental Exposure Studies Using Morris Water Maze

Ordered by direction of expected adverse effect.

Click here (https://hawcproject.org/summary/data-pivot/assessment/126/learning-and-memory-developmental-studies-morris-o/) for interactive graphic.

Apparently identical data were reported in Dong et al. (2015b) and Dong et al. (2015a); data only from Dong et al. (2015b) are presented in figure. Effects are grouped by a solid orange horizontal line by expected adversity direction (increase from reference/control group, then decrease from reference/control group).

Figure 7

Risk of Bias in Studies in Studies Assessing Developmental Exposure to Fluoride

A. Risk of bias in individual studies using the Morris water maze (https://hawcproject.org/summary/visual/151/)[underlined: ;] B. Risk of bias in individual studies assessing classic (https://hawcproject.org/summary/visual/138/) maze performance, passive avoidance or exploration (https://hawcproject.org/summary/visual/138/)[underlined: ;] C. Risk of bias across developmental exposure studies (https://hawcproject.org/summary/visual/152/)

Apparently identical data were reported Dong et al. (2015b) and Dong et al. (2015a) [data only from Dong et al. (2015b) are presented in figure]. Studies at high overall risk of bias excluded (Bǎran-Poesina et al. 2013; Basha et al. 2011; Bera et al. 2007; Hong et al. 2005; Liu 1989; Niu et al. 2014; Niu et al. 2009; Wu et al. 2008; Zhang et al. 2009).

Jiang et al. (2014a) exposed male and female Sprague Dawley rats to ~11.3, 22.6, or 45.3 ppm fluoride beginning at 65 days of age for 10 days, at which time the animals were mated and females continued throughout pregnancy and lactation. The offspring were maintained at the same dose level until 60 days of age. A single value for latency or total distance traveled showed increased time and distance covered to complete the task in all fluoride exposure groups. A single value of swimming speed showed no effect of fluoride exposure. Acquisition of the task over training days was not analyzed. In the memory probe test, the percentage of time spent in the target zone and the percent distance traveled in the target zone, as compared to the remaining area, were less in the fluoride-exposed rats at all concentrations tested.

Other studies used exposure paradigms designed to create fluorosis in the parental population. Gui et al. (2010) exposed a male and female parental generation of Sprague Dawley rats from 30 to 190 days of age to ~30 ppm fluoride in the drinking water. At 190 days of age, rats were mated and continued on ~30 ppm throughout lactation. The F1 offspring were maintained at the same dose level until postnatal assessment. Across 5 days of training in the Morris water maze, all animals showed acquisition (learning) of the task; across training days, however, latency remained longer for the fluoride-exposed offspring. In the memory probe trial, fluoride-exposed offspring showed less time spent in the escape quadrant of the arena and, concurrently, fewer crossings of the location of the previously hidden platform as analyzed by a paired t-test.

Dong et al. (2015b) exposed the male and female parental generation of Sprague Dawley rats from 30 to 300 days of age to 22.6 ppm fluoride in the drinking water. At 300 days of age, rats were mated and continued on 22.6 ppm throughout lactation. The offspring were maintained at the same dose level until postnatal assessment. Latency to reach the hidden platform was longer in fluoride-exposed rats; data on acquisition (learning) of the task were not presented. In the probe trial to assess memory of the platform location, the number of times the rat crossed the previous location of the hidden platform was less in the fluoride-exposed rats. Similar changes were observed in the parental population. Apparently, identical data were reported in a second study from this group (Dong et al. 2015a).

Wei et al. (2014) established fluorosis in 30-day-old male and female Sprague Dawley rats by drinking water exposure to 22.6 ppm fluoride for 150 days. Rats were mated, and exposure continued until PND30. The fluoride-treated offspring took longer to find the hidden platform in the Morris water maze probe test.

#### Classic Maze

Acquisition but impaired performance in the classical maze test was reported in Wistar rats exposed to 45.3 ppm fluoride via drinking water from GD8 to PND105 (El-lethey et al. 2010) (Figure 6, see “maze test” responses). In this study, rats were exposed to 22.6 or 45.3 ppm during GD8 to PND30 or GD8 to PND105 to assess the impact of dose and duration of exposure. The study states an overall effect of fluoride exposure on longer latency and number of errors in locating food. [Variance was not presented for each data point and significance determined by post-hoc analysis for individual days was not clearly indicated.] Performance on the first training day indicated that animals receiving 45.3 ppm fluoride showed longer latencies and greater errors to locate feed. During the 5 days of maze testing, all fluoride-exposed rats displayed learning of the task as demonstrated by acquisition from training day 1 to day 5 and a decrease in the time required and number of errors in locating the feed at the end of the maze. Rats exposed to 45.3 ppm from GD8 to PND105 displayed significantly longer latency to complete the maze with more errors (blind entries) compared to the control group across the entire training session. The change in performance on training day 5 as compared to training day 1, however, suggested that choice errors no longer differed across exposure groups while latency remained longer and errors were more frequent only in the 45.3-ppm group exposed at PND105. No effects were reported for the 22.6-ppm dose group exposed until PND30. Duration of exposure was a significant influence on latency only to complete the maze test. [Based on text in the results and discussion, the authors do not appear to have considered effects in the 22.6-ppm dose groups or the 45.3-ppm GD8 to PND30 group significant.] One other study evaluating maze test performance was excluded based on concerns for overall high risk of bias (Bǎran-Poesina et al. 2013) (Appendix C).

Figure 6

Results from Developmental Exposure Studies in Other Maze, Exploration, and Passive Avoidance Tests

Ordered by direction of expected adverse effect.

Click here (https://hawcproject.org/summary/data-pivot/assessment/126/learning-and-memory-developmental-studies-explor-o/)for interactive graphic. El-lethey et al. (2010) does not report standard errors/standard deviations, so confidence intervals on percent control response cannot be calculated. Effects are grouped by a solid orange horizontal line by expected adversity direction (increase from reference/control group, then decrease from reference/control group, then any change from reference/control group).

#### Passive Avoidance

Wang et al. (2004) treated 30-day-old Wistar rats with fluoride (controls <0.6 ppm; fluoride 43.5 ppm) in the drinking water for 3 months, which were then impregnated and continued on fluoride in the drinking water throughout lactation. Offspring were continued on fluoride for a minimum of 30 days post-weaning. Animals were maintained on a dry food diet containing 25.57 mg/kg fluoride. Learning and memory were assessed by a “step-down” passive avoidance test at 30, 60, or 90 days following cessation of fluoride. The number of errors in the initial training trial was not altered by fluoride exposure. The time to first error in test session showed 30–50% variance, and less time was observed only in the 30-day test group (Figure 6). In the test session, at the 30-day time point only, the number of errors was greater in the fluoride-exposed group (0.666 ± 0.21) as compared to the total absence of errors in the controls. [Results for shock number are not shown in Figure 6 due to inability to calculate a percent change in number of shocks as compared to 0.] Two studies assessing passive avoidance (Bera et al. 2007; Hong et al. 2005) and two studies assessing active avoidance (Bera et al. 2007; Liu 1989) were excluded based on concerns for overall high risk of bias (Appendix C).

#### Exploration

Differences in exploratory activity were reported in adult rats developmentally exposed to fluoride. In this study, female Wistar rats were exposed to 22.6 or 45.3 ppm in the drinking water during GD8 to PND30 or GD8 to PND105 to assess the impact of dose and exposure duration (El-lethey et al. 2010). All rats demonstrated habituation to the open-field arena over 3 days of 3-minute testing; percent change over time representing habituation was not calculated. Rats exposed to 43.5 ppm fluoride via drinking water showed higher activity levels and an increase in the number of freezing instances (time spent not moving). Exploratory activity in an arena allowing for head exploration into holes in the floor (head dipping) showed no significant difference in the change in performance from day 1 to day 2 between dose groups (Figure 6). Across the 2 days, rats exposed to 43.5 ppm until PND150 showed a higher level of exploratory activity measured by rearing and head-dipping as compared to controls. Variance was not presented for each data point, and significance determined by post-hoc analysis at individual days was not indicated. No effects were observed in animals exposed to 22.6 ppm fluoride. [Based on text in the results and discussion, the authors do not appear to have considered effects in the 22.6-ppm dose groups or the 45.3-ppm GD8 to PND30 group significant.] Two studies were excluded based on concerns for overall high risk of bias (Bera et al. 2007; Niu et al. 2014) (Appendix C).

#### Findings from High Risk of Bias Studies

Nine developmental studies were excluded based on concerns for overall high risk of bias (Table 7, see also Appendix D through Appendix J). Of these, three developmental studies were identified that tested concentrations of fluoride at 10 ppm or lower (Bera et al. 2007; Wu et al. 2008; Zhang et al. 2009). In the Bera et al. (2007) study, Harlan Wistar female rats received daily gavage doses of fluoride (7 and 14 ppm) from GD1 throughout lactation to PND9. Control rats received deionized water. Fluoride-exposed offspring showed no differences in multiple endpoints assessing open-field activity. Males showed decreased performance on the roto-rod, passive avoidance, and active avoidance with significance observed at 14 ppm. All animals showed a normal habituation to a novel object. The authors state that female rats receiving 14 ppm showed no shift from trial 1 to trial 2 of the initial novel object exploration test or the preference novel object test; however, data were not presented showing the variance of all data sets. Although the percent change in median response from trial 1 to trial 2 in the 14-ppm exposure group was less for novel object habituation, for novel object preference it was similar to that observed in controls and greater than that seen in the 7-ppm group. No effects were observed in the 7-ppm group. In Morris water maze tests, no statistically significant effects on escape latency were observed following maternal drinking water ingestion at 4.5 ppm fluoride in ICR rats treated from GD7 to birth (Zhang et al. 2009). In Wistar rats exposed to 5 ppm fluoride from GD0 to PND45, Wu et al. (2008) reported no differences in training trials (“learning correct path”) or time required to reach the platform in a water maze task. At 25 ppm fluoride, an increase was observed in latency, but variance was >40%.

Table 7 Learning and Memory Findings from Developmental Exposure Studies Excluded Based on Concern for High Overall Risk of Bias

Reference | Treatment | NOEL | LOEL
1. Bǎran-Poesina et al. (2013) | NMRI mice (F1, n = not reported, ♂♀); drinking water during development with 18.5 or 37.1 ppm (5 or 10 mg/kg-d) [P0 generation from GD8 to PND0; F1 dosing duration unclear] | – | 18.5 ppm (5 mg/kg-d): [underlined: maze test on PND21]: ↑ completion time in ♂♀
2. Basha et al. (2011) | Wistar rat (F1–F3, n = not reported, ♂♀); drinking water during development with 100 or 200 ppm (16 or 32 mg/kg-d) [GD0 to lactation, exposure throughout life in F1 and F2 generations] | – | 100 ppm (16 mg/kg-d): [underlined: T-maze on PND30]: ↑ errors in retention phase and ↑time to reach learning standard (F1–F3 generation)
3. Bera et al. (2007) | Wistar rat (F1, 6–12 ♂♀); gavage to dam with 7 or 14 ppm (1.13 or 2.26 mg/kg-d) [GD0 to PND9] | 7 ppm (1.13 mg/kg-d) | 14 ppm (2.26 mg/kg-d): active avoidance on PND60: ↓percentage of animals displaying conditioned avoidance response in 4th session (no effect in 1st session) passive avoidance on PND60: ↓avoidance latency (no effect on approach latency) [underlined: novel object test on PND40:] ↑time spent exploring familiar object and both objects in trial 2
4. Hong et al. (2005) | Wistar rat (F1, 6 ♂♀); gavage development with 45 ppm (6.9 mg/kg-d) [GD0 to PND90] | – | 45 ppm (6.9 mg/kg-d): [underlined: passive avoidance on PND60–120:] altered response in step down test
5. Liu (1989) | Wistar rat (F1, 7–8 ♂♀); drinking water during development with 13.6 or 27.2 ppm (2.2 or 4.4 mg/kg- d) [GD0 to PND0] | – | 13.6 ppm (2.2 mg/kg-d): active avoidance on ~PND35: ↑latency of conditioned avoidance response on day 9 (no effect on day 2)
6. Niu et al. (2009) | Wistar rat (F1, n = 8, sex not reported); drinking water during development with 68 ppm (11 mg/kg-d) [GD0 to PND21, then directly dosed to 12 weeks] | – | 68 ppm (11 mg/kg-d) [underlined: Y-maze at 6 or 12 weeks:] ↑time to reach learning standard at 12 weeks and total reaction time at 6 weeks
7. Niu et al. (2014) | Kunming mouse (F1, 15 ♂); drinking water during development with 68 ppm (18 mg/kg-d) [GD0 to PND56] | 68 ppm (18 mg/kg-d) [no effects in novel object test on PND56] | –
8. Wu et al. (2008) | Wistar rat (F1, 40 ♂♀); drinking water during development with 1, 5 or 25 ppm (0.2, 1 or 5.3 mg/kg-d) [birth to PND45] | 5 ppm (1 mg/kg-d) | 25 ppm (5.3 mg/kg-d): [underlined: MWM on PND45]: ↑numbers of errors during acquisition phase and ↑time to find platform during probe test
9. Zhang et al. (2009) | ICR rat (F1, 9–10 ♂♀); drinking water during development with 1.13, 2.26 or 4.52 ppm (0.18, 0.36 or 0.71 mg/kg-d) [GD7 to PND0] | 4.52 ppm (0.71 mg/kg-d) [no effects in MWM assessed at 1 month of age] | –

### Exposure during Adulthood

Results show a pattern of findings that suggests an effect on learning and memory when animals were exposed shortly after weaning or in adulthood at dose levels of 2.26 to 226.24 ppm fluoride. Evidence was most abundant and strongest based on findings from the Morris water maze with effects reported at 2.26–62.7 ppm (Dong et al. 2015b; Dong et al. 2015c; Gao et al. 2009a; Gao et al. 2008a; Gao et al. 2008b; Gao et al. 2009b; Jiang et al. 2014b; Li et al. 2015; Liu et al. 2014; Liu et al. 2011; Liu et al. 2010; Liu et al. 2009; Zhu et al. 2012). Support for an effect on learning and memory from the Morris water maze findings was considered moderate-level-of-evidence due to concern for indirectness. The same issues raised in developmental-exposure studies hinder interpretation of behavioral data from adult exposure, that is, secondary effects due to changes in motor or sensory function that could impair the animal’s ability to perform the task. Findings from T-maze, Y-maze, passive avoidance tests, and active avoidance tests supported an effect on learning and memory at 2.71 to 100 ppm but were considered low-level-of-evidence due to concerns for indirectness described above and risk of bias (lack of blinding at outcome assessment and characterization of the test compound)(Chen and Geng 2011; Chioca et al. 2008; Li et al. 2015; Niu et al. 2008; Raghu et al. 2013; Shen et al. 2004; Sun et al. 2008; Wang et al. 2006; Wu et al. 2006; Xu et al. 2001; Zhang et al. 2013; Zhang et al. 1999). Additional studies targeted to address these issues are required to achieve higher confidence in learning or memory impairments. Studies also are required that provide quantitative measures such as the effect sizes, point of departure, identification of NOEL or LOEL doses, or parameters for benchmark dose analysis. Most of the studies that indicated an effect of fluoride exposure on learning and memory were maze or avoidance studies. As in all learning tests, assessment requires measuring the acquisition of the task (increase in performance over time). When such data were available, fluoride-exposed animals often demonstrated acquisition similar to the controls. In these studies, a pattern emerged suggesting the need for (1) further evaluation of an effect on learning and memory using paradigms that are not influenced by motor functions or anxiety/fear reactions or (2) design of studies to interrogate the underlying effect influencing the performance more closely.

Most studies used rats (Sprague Dawley, Wistar); use of mouse models (BALB/c, ICR, Kunming) was more limited. No studies specifically evaluated a male/female difference in response to fluoride exposure, often only males were examined, males and females were pooled or, when sex was considered, unequal group sizes were compared. Thus, determining sex or species/strain difference in response to fluoride exposure was not clear. From the available data, the lowest concentration effects were observed in the 2.26- to 2.71-ppm range in mice (BALB/c in Morris water maze; Kunming in Y-maze) (Liu et al. 2014; Xu et al. 2001) and rats (Sprague Dawley in Morris water maze) (Liu et al. 2011; Liu et al. 2010; Liu et al. 2009). The group size used in most studies ranged between 6 and 10 animals with a limited number of studies using as few as 3 or as many as 30. Based on variability in the control groups, these group sizes were considered statistically underpowered to detect <10% or <20% change from controls for most behavioral endpoints. When measured, the baseline concentration of fluoride in control drinking water ranged from 0.23 to 1 ppm (Chioca et al. 2008; Gao et al. 2009a; Gao et al. 2008b; Liu et al. 2011; Liu et al. 2010; Liu et al. 2009; Raghu et al. 2013).

#### Morris Water Maze

The Morris water maze has been used to assess effects of adult exposure to 2.26–62.68 ppm fluoride (Figure 8). One study was conducted in BALB/c mice (Liu et al. 2014), while the others used Sprague Dawley rats (Dong et al. 2015c; Gao et al. 2009a; Gao et al. 2008a; Gao et al. 2008b; Gao et al. 2009b; Jiang et al. 2014b; Liu et al. 2011; Liu et al. 2010; Liu et al. 2009; Zhu et al. 2012) or Wistar rats (Li et al. 2015). In general, effects observed were related to latency (time) for the animal to reach an escape platform. Within a study, Morris water maze endpoints were typically internally consistent. If a slower escape time was observed at the end of acquisition phase, the animals also displayed fewer platform crossings and spent less time in the target quadrant during the probe test. With latency at the end of training serving as a critical effect, the NOEL was 0.9 ppm fluoride (Liu et al. 2014) and the LOEL was 2.26 ppm fluoride following 30 days of treatment in BALB/c male mice (Liu et al. 2014) and 6 months of treatment in Sprague Dawley rats in several studies from the same research team (Liu et al. 2011; Liu et al. 2010; Liu et al. 2009). None of the adult exposure Morris water maze studies were excluded based on having a high overall risk of bias and no serious concerns were present (Figure 9). In two instances, identical data appear to have been reported in separate publications^11^ [Dong et al. (2015a); Dong et al. (2015b) and Liu et al. (2011); Liu et al. (2009)]. For these studies, results as reported in the earliest publication are discussed below.

11 Duplicate data from Dong et al. (2015a) for the P0 generation appear to be reported in Dong et al. (2015b). Only results from Dong et al. (2015a) are discussed. Some data from Liu et al. (2009) also are presented in Liu et al. (2011). Specifically, the values for escape time and acquisition on day 6 are identical, although the animal numbers per group differ. Duplicate results are summarized as part of Liu et al. (2009).

Figure 8

Results from Adult Exposure Studies Using Morris Water Maze

Ordered by direction of expected adverse effect.

Click here (https://hawcproject.org/summary/data-pivot/assessment/126/learning-and-memory-morris-water-maze-adult-ordere/) for interactive graphic.

Some data from Liu et al. (2009) also are presented in Liu et al. (2011) (escape time, acquisition, day 6), findings are presented under Liu et al. (2009) in figure. Apparently identical data were reported in Dong et al. (2015b) and Dong et al. (2015a); only data from Dong et al. (2015b) are presented in figure. Effects are grouped by a solid orange horizontal line by expected adversity direction (increase from reference/control group, then decrease from reference/control group).

Figure 9

Risk of Bias in Studies Assessing Adult Exposure to Fluoride Using the Morris Water Maze

(A) Risk of bias at the individual study level. (https://hawcproject.org/summary/visual/140/) (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/141/)

The one study conducted in BALB/c male mice examined effects following a 30-day exposure (4–8 weeks of age) to 0.9, 2.26, and 4.52 ppm fluoride (Liu et al. 2014). In the pretest, no significant differences were noted in the initial swimming speed of the mice. In mice exposed to 2.26 and 4.52 ppm, acquisition was demonstrated but the shape of the acquisition curve was altered with an overall higher latency. In the probe test, mice exposed to 2.26 and 4.52 ppm spent less time in the target escape quadrant and showed fewer crossings over the learned escape platform location. No effects were observed at 0.9 ppm fluoride. At 4.52 ppm, authors reported clinical signs in the animals (curled up bodies, less movement, slightly wrinkled fur, and fluorosis symptoms in incisor teeth manifest as pale yellow plaques).

Ten studies assessed the effects of adult exposure in rats (primarily Sprague Dawley) lasting for 2 to 6 months at concentrations of 2.26 to 62.68 ppm fluoride (Dong et al. 2015c; Gao et al. 2009a; Gao et al. 2008a; Gao et al. 2008b; Gao et al. 2009b; Jiang et al. 2014b; Li et al. 2015; Liu et al. 2011; Liu et al. 2010; Liu et al. 2009; Zhu et al. 2012). Seven of 11 studies appear to have represented a body of work conducted by a research team in the Department of Pathology and Molecular Biology at Guiyang Medical College (Dong et al. 2015c; Gao et al. 2009a; Gao et al. 2008b; Liu et al. 2011; Liu et al. 2009). Fluoride concentrations in the control drinking water ranged from 0.23–1 ppm (Gao et al. 2009a; Liu et al. 2011; Liu et al. 2009).

The lowest fluoride drinking water concentrations (2.26, 22.6 ppm) were examined in studies by the Guiyang Medical College team [(Gao et al. 2009a; Liu et al. 2011; Liu et al. 2010; Wu et al. 2008); 2.26 and 22.6 ppm] and by Zhu et al. (2012)(2.26, 4.52, and 9.05 ppm). Gao et al. (2008b) exposed male and female (pooled for analysis) Sprague Dawley rats to 2.26 or 22.6 ppm fluoride via drinking water for 3 months and reported a significantly longer escape latency at the end of the acquisition phase in the 22.6-ppm group. No effect was observed in platform crossings or time in target zone in the probe test in any group. Zhu et al. (2012) reported that a 30-day exposure of male and female Sprague Dawley rats (combined for the analysis) to 9.05 ppm resulted in a longer latency to reach the hidden platform across all days of training in a Morris water maze task. Acquisition of the task was not analyzed nor was a memory probe test conducted. No effect was observed at exposure levels of 2.26 or 4.52 ppm.

Extending the duration of exposure in Sprague Dawley rats to 6 months indicated effects on Morris water maze at 2.26 ppm in Liu et al. (2011); Liu et al. (2010); Liu et al. (2009). Acquisition of the task was demonstrated by a progressive decrease in escape latency over the 5 days of training in all groups. A general pattern of longer latencies was reported in fluoride-exposed groups as compared to controls as early as day 2 of training (Liu et al. 2009) (Figure 8). Data were analyzed each day independently and not as a progression over time. In Liu et al. (2010), the probe test suggested a higher latency for the animals to reach the location of the previously hidden platform at both dose levels (Figure 8). [Some data presented in Liu et al. (2011) appeared identical to those presented in Liu et al. (2009), and results are summarized as part of Liu et al. (2009).] Using the same dosing paradigm, other studies by the Guiyang Medical College investigators reported no significant effects on Morris water maze latency or probe test at 2.26 ppm (Gao et al. 2009a; Gao et al. 2008a; Gao et al. 2008b). In rats exposed to 22.6 ppm fluoride, escape latency was longer at the end of Morris water maze training and no effect was observed on the probe test. Data on acquisition over training were not provided. In a study by Li et al. (2015), no statistically significant effects were observed on Morris water maze endpoints in Wister rats exposed to 22.6 ppm fluoride for 3 months.

At higher fluoride concentrations (50–62.68 ppm), longer escape latency at the end of the Morris water maze training session and less preference for the hidden platform quadrant during the probe test have been reported (Dong et al. 2015c; Gao et al. 2008b; Jiang et al. 2014b). [In these studies, the fluoride-exposed group was used as a control to examine neuroprotective potential for therapeutics. Such data appear identical in Dong et al. (2015a) and Dong et al. (2015b) and, thus, are not considered as independent findings.] In Jiang et al. (2014b), the effects on escape latency, platform crossing, and time spent in target quadrant also were impaired when assessed 1 week after the acquisition phase, leading the authors to conclude that longer-term memory could be impacted.

Learning is defined as an increase in performance on a task over time and is experimentally measured in animal studies by generating an acquisition curve. Several adult Morris water maze studies did not present acquisition data, instead relying on performance at a single time point at the end of training (Gao et al. 2009a; Gao et al. 2008a; Liu et al. 2011) or averaged over the full training period (Dong et al. 2015c). This approach raises concern for data interpretation. Using terminal performance (latency or distance traveled) as an endpoint of learning—in isolation from previous trials—fails to consider differences in baseline performance that would translate to later evaluations. In the study by Gao et al. (2009a), young adult Sprague Dawley rats (male and female) received four training trials a day for 5 days. Although the four trials per day were reportedly averaged for statistical analysis, latency only on day 6 was evaluated followed by a probe trial on day 7. Escape latency on day 6 showed no difference between controls and the 2.26-ppm dose group and a significant increase was observed in the 22.6-ppm dose group. No differences across groups were observed in the probe test.

Li et al. (2015) treated 5-week-old male Wistar rats with distilled water or 22.6 ppm fluoride in the drinking water for 3 months. Rats were allowed 2 training days of 8 trials per day followed by a probe test on day 3. Escape latency on each day and probe test performance were not statistically significant between groups. In the Morris water maze studies that did present acquisition data over 4 or 5 days, NTP calculated difference scores between the start and end of the acquisition phase to examine the progressive change in the animal’s performance on the task. Effects on escape latency were more likely apparent at the end of training and either were not observed on the first day (Liu et al. 2014; Liu et al. 2010; Liu et al. 2009) or were observed but were smaller on the first day than on the last (Gao et al. 2009b; Zhu et al. 2012). With training, the differences in absolute latencies between groups could be magnified. Examining acquisition calculated as a percent change (increased performance) over time revealed that, in approximately half the studies, the change over time was equivalent to controls (Gao et al. 2009b; Jiang et al. 2014b; Liu et al. 2010; Liu et al. 2009) even though actual latency was higher. Other studies indicate impaired learning acquisition. In BALB/c mice, Liu et al. (2014) showed an approximate 45% change over time in latency in controls exposed to 0.9 ppm fluoride for 30 days. Mice exposed to 2.26 ppm showed an approximate 15% change while those exposed to 4.52 ppm showed an approximate 7% change over time. In Sprague Dawley rats exposed to fluoride for 3 months, Zhu et al. (2012) reported no statistically significant change in latency over Morris water maze training sessions. An approximate 50% change in latency was observed for controls and the 2.26-ppm dose group, 45% for the 4.52-ppm group, and 30% for the 9.05-ppm dose group.

#### T- Maze and Y-Maze

Learning can be assessed experimentally by examining behavior improvement over training sessions and determining whether a memory of the task develops that enables better performance on subsequent sessions or following an interval of time without a continuation of training trials. T-maze learning is estimated based on spontaneous alternation between arm entries. In the T-maze, adult male Wistar rats exposed to 45.3 ppm fluoride for 30 days showed an arm bias in the spontaneous alternation paradigm and a decrease in exploratory activity (Raghu et al. 2013) (Figure 10). In the same study using a rewarded alternation paradigm, the percentage of correct responses in exposed rats decreased. The influence of the baseline arm bias on the choice of correct arm was not evaluated. In Wistar rats exposed to 22.6 ppm fluoride for 3 months, no differences were observed in alternation rate in a Y-maze (Li et al. 2015).

Figure 10

Results from Adult Exposure Studies Using Y- Maze and T-Maze

Ordered by direction of expected adverse effect.

Click here (https://hawcproject.org/summary/data-pivot/assessment/126/learning-and-memory-y-maze-and-t-maze-adult-ordere/)for interactive graphic.

Effects are grouped by a solid orange horizontal line by expected adversity direction (increase from reference/control group, then decrease from reference/control group, then any change from reference/control group).

Using a cued (light)/shock-reinforced Y-maze paradigm to assess learning, the number of choice errors or the number of training trials to reach a predetermined learning criterion was assessed in mice or rats exposed to 0.45–90.5 ppm fluoride (Figure 10). Impaired performance was reported for exposure durations between 30 days and 6 months. Exposure to 2.71 ppm for 8 weeks in mice and 22.6 ppm for 6 months in rats resulted in a performance deficit (Figure 10) measured by number of choice errors or number of training trials to reach learning criteria (Chen and Geng 2011; Niu et al. 2008; Shen et al. 2004; Wang et al. 2006; Xu et al. 2001; Zhang et al. 2013; Zhang et al. 1999).^12^

12 In several studies (Chen and Geng 2011; Shen et al. 2004; Wang et al. 2006; Xu et al. 2001), whether SD or SEM was reported is unclear. Typically, SD was assumed, based on the magnitude of the values and results of authors’ statistical analysis. In Zhang et al. (2013), values were assumed to be SEMs.

In a cued Y-maze with shock reinforcement, 30-day-old ICR mice exposed to fluoride for 10 weeks showed a delay in learning (Zhang et al. 1999). At exposure levels of 4.52 ppm fluoride, mice displayed a delay in reaching a criterion of 90% correct choice rate within a session. The mice required approximately 80% more trials to achieve the criterion, as compared to controls. No effect was observed at dose levels of 0.45 and 2.26 ppm. After a 24-hour interval, mice in all groups showed a similar level of performance of 70%. In another study from what appears to be the same research group, Xu et al. (2001) exposed male Kunming mice to 2.71 ppm fluoride for 8 weeks and reported more training runs were required to meet learning criteria, but the percentage of total correct responses was unchanged (Figure 10).

At higher doses, male Wistar rats exposed to 22.6, 45.2, or 67.9 ppm fluoride for 6 months needed more Y-maze training sessions to meet learning criteria; however, the number of correct responses on the last day of training was similar to controls (Chen and Geng 2011). Shen et al. (2004) reported a similar outcome with 5 months of exposure to 67.9 ppm, with a twofold increase in the number of trials to reach criteria and 50% decrease in percentage of correct responses in the memory trial. Niu et al. (2008) examined effects of a 30-day exposure to 67.9 ppm fluoride in male and female (combined) Wistar rats on Y-maze performance. Training consisted of 20 trials per day until rats achieved a criterion of 90% correct choices within a session. Control rats required 3 days of training, while the 67.9-ppm group required 5 days of training. [The authors state “rats in the three treatment groups spent more days in meeting the learning standard of the Y-maze test” but the effect is not indicated in the figure as being statistically significant.] Rats in the 67.9-ppm group made significantly more errors at the start of training, but the number of errors showed a progressive decline over test days in both groups and by the last training day, no group differences were evident in error number or total reaction time. [Variance for error numbers on day 5 was not presented.]

Wang et al. (2006) reported a longer latency in the Y-maze in Wistar rats exposed by gavage to 45.2 or 90.49 ppm fluoride for 5 months. Zhang et al. (2013) exposed male Wistar rats to daily gavage delivery of 45.2 ppm fluoride beginning at 6 weeks of age and continuing for 3 months. The number of times the rat entered into the correct arm of the Y maze over a 20-trial session was recorded. After 9 training sessions, the retest was conducted 14 days later. All animals displayed a similar level of acquisition over the training sessions. Although not statistically analyzed by the authors, performance on the initial training day was similar. The number of times the rat entered the correct arm on the last day of training was significantly less in the fluoride-exposed rats. This difference was approximately 15%. Memory of the task assessed 2 weeks later showed an approximately 30% difference, interpreted as lower retention in the fluoride exposed rats.

The following T-maze, Y-maze, or other maze studies were excluded from the primary analysis because of concerns for risk of bias in several critical domains (Basha and Sujitha 2012; Bhatnagar et al. 2002; Elliott 1967; Jetti et al. 2016; Zhang et al. 2001) (see Appendix C for rationale). Except for Zhang et al. (2001), the excluded studies used high concentrations of fluoride (>67 ppm). Across the remaining studies, risk of bias was a “serious” concern based on issues regarding adequate exposure characterization and lack of blinding during outcome assessment (Figure 11). Exclusion of Zhang et al. (2001) did not appreciably alter conclusions because the authors reported findings consistent with those described above for Zhang et al. (1999) and Xu et al. (2001).

Figure 11

Risk of Bias in Studies Assessing Adult Exposure to Fluoride Using the T- or Y-Maze

(A) Risk of bias at the individual study level. (https://hawcproject.org/summary/visual/146/) (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/153/) Studies at high overall risk of bias excluded (Basha and Sujitha 2012; Bhatnagar et al. 2002; Elliott 1967; Jetti et al. 2016; Zhang et al. 2001).

##### Passive and Active Avoidance

In avoidance paradigms, animals are required to learn an association with an adverse event (shock) and to adjust behavior to avoid the event.

###### Passive Avoidance

In Raghu et al. (2013), male Wistar rats (n = 6) 30 days of age received 100 ppm fluoride in the drinking water for 30 days. No differences were observed during the initial exploration/training phase and in the retention phase; time spent in the unsafe compartment decreased by 60% in controls and 35% in the exposed animals [details of testing paradigm not described in methods or in the cited textbook] (Figure 12). Wu et al. (2006) exposed 30-day-old male and female Wistar rats to 45.3 ppm fluoride for up to 90 days. At 30, 60, and 90 days of exposure, rats showed no difference in errors, defined as movement from rubber mat to electrified bar, during the initial training or retention sessions; they did, however, show a shorter latency in making the first error response in the retention trial (Figure 12 shows data from 30 days only).

Figure 12

Results from Adult Exposure Studies Using Active and Passive Avoidance Tests

Ordered by direction of expected adverse effect.

Click here (https://hawcproject.org/summary/data-pivot/assessment/126/learning-and-memory-active-and-passive-avoidance-o/)for interactive graphic.

Effects are grouped by a solid orange horizontal line by expected adversity direction (increase from reference/control group, then decrease from reference/control group, then any change from reference/control group).

Two studies assessing passive avoidance were excluded from the analysis due to concerns for risk of bias (Jain et al. 2015; Jetti et al. 2016). Jetti et al. (2016) used the same model system Raghu et al. (2013) used (appear to be the same research group) and found similar results in male Wistar rats exposed to 100 ppm fluoride for 30 days. Jain et al. (2015) reported a longer retention latency in young Wistar rats (sex not reported) treated with 1.36 ppm fluoride for 60 days beginning on PND18 [details on how or what retention latency refers to were not reported]. Across the remaining studies, concerns for risk of bias were “serious,” based primarily on issues regarding adequate characterization of the exposure and lack of blinding during outcome assessment (Figure 13).

Figure 13

Risk of Bias in Adult Exposure Studies Using Active and Passive Avoidance Tests

(A) Risk of bias at the individual study level. (https://hawcproject.org/summary/visual/147/) (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/154/) Studies at high overall risk of bias excluded (Jain et al. 2015; Jetti et al. 2016).

###### Active Avoidance

The latency to respond to a cued shock decreased over training trials in controls (0.7 ppm fluoride) and in adult male Wistar rats exposed to 22.6 or 45.3 ppm fluoride for 30 days (Chioca et al. 2008). The data showed a high degree of variance. Control animals learned to shift their response pattern to avoid the shock, while a larger proportion of the fluoride-exposed animals displayed an escape, rather than avoidance, response or failed to escape the shock (Figure 12).

In Sun et al. (2008), 60-day-old male and female Kunming mice (n = 10−12) were exposed to 10, 50, or 100 ppm fluoride in drinking water for 6 months. Using avoidance response as a measure of learning, acquisition over five sessions was demonstrated in all exposure groups. Fluoride-exposed mice, however, took longer to complete the 150 conditioned response trials on the last training day, and all fluoride-exposed mice showed a lower level of avoidance response than controls. When data were averaged across the 150 trials, fluoride-exposed mice in all groups required more runs to display the conditioned avoidance response, took longer to perform the task, and showed a lower level of avoidance responses (Figure 12).

#### Exploration

Exploration in animals can reflect a learning of the environment but also can influence performance on latency or attention-dependent learning tasks. In Liu et al. (2014) 1-month old BALB/c male mice were exposed to fluoride (0.9, 2.26, or 4.52 ppm) via drinking water for 4 weeks. Locomotor activity and rearing were not significantly different across groups, with all groups displaying habituation to the novel arena environment over time. In a test paradigm for novel object recognition, animals showed similar exploratory activity levels and lack of preference for objects during training. When a preference of familiar versus novel was examined, total time spent with novel object was similar across groups. Preference for the novel object, however, was reduced by approximately 20% in the 2.26- and 4.52-ppm groups. Han et al. (2014) exposed adult male Kunming mice to 11, 22, or 45 ppm fluoride for 180 days. No effects were observed on open-field ambulatory or rearing levels, and the time spent in different quadrants of the arena was similar across groups. In a novel object recognition paradigm, the predicted pattern for controls—to show a preference for a novel object over a familiar object—was not observed. This pattern also was not observed in the 11- or 22-ppm fluoride-exposed group, while, in the 45-ppm group, a significant preference for the familiar object was observed. Because of the absence of the predicted control behavior, this study is not included (Figure 14). At a very high concentration of 226 ppm for 60 days, reduced exploratory motor activity was reported in male Wistar rats (Ekambaram and Paul 2003) (Figure 14). Across studies, “no serious” concerns for risk of bias were evident (Figure 15).

Figure 14

Results from Adult Exposure Studies Using Exploration and Operant Behavior Tests

Ordered by direction of expected adverse effect.

Click here (https://hawcproject.org/summary/data-pivot/assessment/126/learning-and-memory-exploration-and-operant-beha-o/)for interactive graphic.

Effects are grouped by a solid orange horizontal line by expected adversity direction (increase from reference/control group, then decrease from reference/control group, then any change from reference/control group).

Figure 15

Risk of Bias in Adult Exposure Studies Using Exploration and Operant Behavior Tests

(A) Risk of bias at the individual study level. (https://hawcproject.org/summary/visual/148/) (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/149/) Studies at high overall risk of bias

excluded (Han et al. 2014).

#### Operant Behavior

#### Findings from High Risk of Bias Studies

Seven adult studies were excluded based on concerns for overall high risk of bias (Table 8). In general, these studies provided evidence to support an effect on learning and memory at high concentrations. Of these, two studies tested concentrations of fluoride at 10 ppm or lower (Elliott 1967; Zhang et al. 2001). In Elliott (1967), no effects were observed in Hooded rats treated for 4 months with 4.24 or 42.4 ppm in an elevated multiple T-maze. In Zhang et al. (2001), male Kunming mice exposed for 8 weeks to 2.26 or 4.52 ppm fluoride required more training runs to reach the learning standard although percentage of correct responses was not affected 24 hours after reaching learning criteria. No effects were observed in the 0.45-ppm group.

Table 8 Learning and Memory Findings from Adult Exposure Studies Excluded Based on Concern for High Overall Risk of Bias

Reference | Treatment | NOEL | LOEL
1. Basha and Sujitha (2012) | Wistar rat (adult, 6 ♂); drinking water for 30 days with 271 ppm (40 mg/kg-d) | – | 271 ppm (40 mg/kg-d): [underlined: T-maze]: ↑ time to reach learning standard during retention phase (but no effect on error number during acquisition or retention phase or time to reach standard during acquisition phase)
2. Bhatnagar et al. (2002) | Swiss albino mice (adult, 5 ♀); drinking water for 30 days with 14.7 ppm (54.3 mg/kg-d) | – | 14 ppm (54.3 mg/kg-d): “[underlined: simple maze” test]: ↑ latency to complete
3. Elliott (1967) | Hooded rat (adult, 15 ♂); drinking water for 4 months with 4.24 or 42.4 ppm (0.6 or 6 mg/kg-d) | 42.4 ppm (6 mg/kg-d) [no effects on error number or time to complete maze test] | –
4. Han et al. (2014) | Kunming mouse (adult, 15 ♂); drinking water for 5 months with 11, 22, or 45 ppm (2.8, 5.6, or 11.5 mg/kg-d) | 22 ppm (5.6 mg/kg-d) | 45 ppm (11.5 mg/kg-d) [underlined: novel object test]: ↓ discrimination index (no other effects were observed in novel object test)
5. Jain et al. (2015) | Wistar rat (adult, n = not reported, sex not reported) drinking water for 60 days with 11.8 ppm (1.8 mg/kg-d) | – | 11.8 ppm (1.8 mg/kg-d): [underlined: passive avoidance]: ↑ latency time during retention phase
6. Jetti et al. (2016) | Wistar rat (adult, 6 ♂); drinking water for 4 months with 100 ppm (14.75 mg/kg-d) | – | 100 ppm (14.75 mg/kg-d): [underlined: T-maze]: ↓ number correct choices and exploratory activity, ↑ number of spontaneous alterations. [underlined: passive avoidance:] ↑ retention time in small compartment
7. Zhang et al. (2001) | Kunming mouse (adult, 12-21 ♂); drinking water for 8 weeks with 0.45, 2.26 or 4.52 ppm (0.12, 0.58, or 1.16 mg/kg-d) | 0.45 ppm (0.12 mg/kg-d) | 2.26 ppm (0.58 mg/kg-d) [underlined: Y-maze]: ↑ number of training runs to reach learning standard (no effect on percentage of correct responses 24 hours after mastering learning standard)

### Exposure at Less Than 4 ppm

The 2006 NRC report focused on effects in the 2- to 4-ppm range. Most fluoride neurobehavioral studies identified in the current review used higher fluoride concentrations. Findings at <4 ppm across all behavioral tests (learning and memory, motor function, anxiety, depression, etc.) are summarized in Figure 16 (Bartos et al. 2015; Gao et al. 2009a; Gao et al. 2008a; Gao et al. 2008b; Liu et al. 2014; Liu et al. 2011; Liu et al. 2010; Liu et al. 2009; Xu et al. 2001; Zhang et al. 1999; Zhu et al. 2012). Only one study included developmental exposure (Bartos et al. 2015).

Figure 16

Results from All Studies Assessing Effects at ≤4 ppm

Ordered by direction of expected adverse effect.

Click here (https://hawcproject.org/summary/data-pivot/assessment/126/all-behavior-less-or-equal-4-ppm-ordered/)for interactive graphic.

Studies at high overall risk of bias excluded. Data not shown for Morris water maze data on acquisition day 1. Except for the Gao et al. (2009a) study, acquisition day 1 responses were not altered (escape time was significantly longer on acquisition day 1, but not on day 5). Some data from Liu et al. (2009) also are presented in Liu et al. (2011). Specifically, the values for escape time and acquisition on day 6 are identical, although the animal numbers per group differ. Duplicate results are summarized as part of Liu et al. (2009). Effects are grouped by a solid orange horizontal line by expected adversity direction (increase from reference/control group, then decrease from reference/control group, then any change from reference/control group).

The lowest concentration tested was 0.9 ppm in adult male BALB/c mice for 30 days and no effects were reported (Liu et al. 2014) for locomotor activity, tail suspension immobility time, elevated plus maze, swimming speed, or learning and memory (Morris water maze, novel object recognition). Five studies, four of which were published after the 2006 NRC review, reported learning and memory deficits in mice or rats at 2.26−2.71 ppm, including impaired performance in the Morris water maze (Liu et al. 2014; Liu et al. 2011; Liu et al. 2010; Liu et al. 2009), Y-maze (Xu et al. 2001), and novel object recognition tests (Liu et al. 2014). Liu et al. (2014) showed no alterations in swimming speed prior to Morris water maze testing.

Liu et al. (2014) also reported fewer locomotion events in an activity cage test and a longer tail suspension immobility time (taken as indicative of depression, although it can reflect decreased muscle strength) in BALB/c mice exposed to 2.26 ppm or 4.52 ppm for 30 days. Effects on immobility time in a forced swim test as a measure of depression were observed in the 4.52-ppm dose group. Bartos et al. (2015) did not assess learning and memory but reported delayed eye opening in F1 male and female offspring of Wistar rats treated from GD0 to PND21 with 2.26 ppm fluoride with no differences noted in other neurodevelopmental landmarks. At 90 days of age, these offspring demonstrated lower activity levels (15 min) and an increase in entries and time spent in the open arm of an elevated plus maze. Several studies examined dose levels at 2.26 ppm and reported no statistically significant effects on behavioral assessments (Gao et al. 2009a; Gao et al. 2008b; Zhang et al. 1999; Zhu et al. 2012). The effects on Morris water maze at 2.26 ppm were not consistent. Several of these studies appear to have been conducted by the same research group using a very similar experimental paradigm; the authors found effects in some studies (Liu et al. 2011; Liu et al. 2010; Liu et al. 2009) but not in others (Gao et al. 2009a; Gao et al. 2008a; Gao et al. 2008b).

Risk of bias was of no serious concern among these studies (Figure 17). Reporting quality was an issue, especially regarding a lack of information on concealment during allocation of animals to study groups and blinding of research personnel during the study. Blinding at outcome assessment was not considered consistently, which represents a major concern for any endpoint obtained by observational methods. Endpoints obtained using computer-assisted equipment and measurements were of lesser concern for blinding. One of the two studies considered to have “probably high risk of bias” due to lack of blinding at outcome assessment reported effects at 2.26 ppm (Xu et al. 2001). Information on source and purity of the fluoride was not reported consistently. Several studies that did not report this information, however, measured levels of fluoride in serum, urine, or bone and observed dose-gradients in internal exposure levels (Appendix U).

Figure 17

Risk of Bias Ratings for Studies ≤4 ppm

(A) Risk of bias at the individual study level. (https://hawcproject.org/summary/visual/133/) (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/134/) Studies with high risk of bias excluded (Elliott 1967; Wu et al. 2008; Zhang et al. 2009; Zhang et al. 2001).

#### Findings from High Risk of Bias Studies (<5 ppm)

Four studies assessing fluoride levels <5 ppm were excluded based on concerns for overall high risk of bias (Elliott 1967; Wu et al. 2008; Zhang et al. 2009; Zhang et al. 2001); (Table 9). Inclusion of these studies would not have appreciably influenced the conclusions described above. In general, these studies did not provide support for effects at low concentrations. Either no significant effects were observed (Elliott 1967) or effects appeared sporadically. In Zhang et al. (2009), no effects were observed in the Morris water maze at concentrations up to 4.52 ppm in F1 male and female ICR rats of dams treated from GD7 to PND0. This study did report statistically significant decreases in locomotor activity in the open field test: Fewer grid entries occurred at 3 minutes at 2.26 ppm (but not at 1 minute) and fewer rearing events occurred at 1.13 ppm (but not at 2.26 or 4.52 ppm). Wu et al. (2008) found a change in grooming behavior (increased face scrubbing events) at 1 ppm in the open field test in F1 male and female Wistar rats treated from GD0 to PND45 with 1, 5, or 25 ppm fluoride. No other open-field endpoints were altered at 1 ppm, and no effects at this concentration were observed in the Morris water maze, tests for pain response, reflex and sensory development (surface righting, cliff avoidance, negative taxis), physical development (pinna detachment, incisor eruption,), or motor coordination.

Table 9 Findings from Studies Testing <5 ppm Fluoride Excluded Based on Concern for High Overall Risk of Bias

Reference | Treatment | NOEL | LOEL
1. Elliott (1967) | Hooded rat (adult, 15 ♂); drinking water for 4 months with 4.24 or 42.4 ppm (0.6 or 6 mg/kg-d) | 42.4 ppm (6 mg/kg-d) [no effects on error number or time to complete maze test] | –
2. Wu et al. (2008) | Wistar rat (F1, 40 ♂♀); drinking water during development with 1, 5, or 25 ppm (0.2, 1, or 5.3 mg/kg-d) [birth to PND45] | – | 5 ppm (1 mg/kg-d): [underlined: activity]: ↑activity time (no effect at 25 ppm), ↓number of squares traveled in open field test most endpoints not altered at 5 ppm; decreased face scrubbing observed at 1 ppm in open field
3. Zhang et al. (2001) | Kunming mouse (adult, 12−21 ♂); drinking water for 8 weeks with 0.45, 2.26, or 4.52 ppm (0.12, 0.58, or 1.16 mg/kg-d) | 0.45 ppm (0.12 mg/kg-d) | 2.26 ppm (0.58 mg/kg-d) [underlined: Y-maze]: ↑number of training runs to reach learning standard (no effect on percentage of correct responses 24 hours after mastering learning standard)
4. Zhang et al. (2009) | ICR rat (F1, 9−10 ♂♀); drinking water during development with 1.13, 2.26, or 4.52 ppm (0.18, 0.36, or 0.71 mg/kg-d) [GD7 to PND0] | – | 1.13 ppm (0.71 mg/kg-d) [underlined: open field]: ↑number of rearing events (no effect at 2.26 or 4.52 ppm) no effects in Morris water maze at any dose level

### Quality of Evidence

Results show low-to-moderate level-of-evidence in developmental and adult exposure studies for a pattern of findings suggestive of an effect on learning and memory (Table 10). The evidence was strongest for adult exposure studies using the Morris water maze. Level-of-evidence conclusions were rated down due to concern for indirectness and risk of bias.

Table 10 Learning and Memory (Quality of Evidence and Summary of Findings)

Studies | Risk of Bias | Inconsistency | Indirectness | Imprecision | Publication Bias | Magnitude | Dose Response | Quality of Evidence
Impaired Learning and Memory (Developmental Exposure)
6 Studies (MWM, Passive Avoidance, Exploration) | Serious^1^ | No serious | Serious indirectness^2^ | No serious | Not detected^3^ | No basis for upgrade | No basis for upgrade^4^ | ⊕⊕⊖⊖ Low risk of bias and indirectness
Impaired Learning and Memory (Adult Exposure)
14 Studies (MWM, Exploration, Operant Behavior) | No serious | No serious | Serious indirectness^2^ | No serious | Not detected^3^ | No basis for upgrade | No basis for upgrade^4^ | ⊕⊕⊕⊖ Moderate indirectness
12 Studies (T-maze, Y-maze, Passive Avoidance, Active Avoidance) | Serious^1^ | No serious | Serious indirectness^2^ | No serious | Not detected^3^ | No basis for upgrade | No basis for upgrade^4^ | ⊕⊕⊖⊖ Low risk of bias and indirectness

32 Studies: Quality of evidence: low (⊕⊕⊖⊖) to moderate (⊕⊕⊕⊖). Additional studies are required to have higher confidence in the specificity of the responses as learning or memory impairments and in quantitative measures, such as the effect sizes, identification of NOEL or LOEL doses, or parameters for benchmark dose analysis.

Developmental: (Dong et al. 2015c; El-lethey et al. 2010; Gui et al. 2010; Jiang et al. 2014a; Wang et al. 2004; Wei et al. 2014). Duplicate data from Dong et al. (2015b) appear to be reported in another study from this group Dong et al. (2015a).

Adult (MWM, exploration, operant behavior): (Dong et al. 2015c; Ekambaram and Paul 2003; Gao et al. 2009a; Gao et al. 2008b; Gao et al. 2009b; Jiang et al. 2014b; Li et al. 2015; Liu et al. 2014; Liu et al. 2011; Liu et al. 2010; Liu et al. 2009; Whitford et al. 2009; Zhu et al. 2012). Duplicate data from Dong et al. (2015a) for the P0 generation appear to be reported in another study from this group Dong et al. (2015b).

Adult (T-maze, Y-maze, passive avoidance, active avoidance): (Chen and Geng 2011; Chioca et al. 2008; Li et al. 2015; Niu et al. 2008; Raghu et al. 2013; Shen et al. 2004; Sun et al. 2008; Wang et al. 2006; Wu et al. 2006; Xu et al. 2001; Zhang et al. 2013; Zhang et al. 1999).

^1^ Only one of the six developmental studies appeared to control for litter effects, a critical risk of bias factor in developmental exposure studies. In the adult studies for T-maze, Y-maze, passive avoidance, or active avoidance, the lack of blinding at outcome assessment and adequate characterization of the fluoride treatment were concerns.

^2^ Studies reported impaired learning and memory in fluoride-exposed animals that could reflect a motor activity deficit; however, motor function/activity levels were often not assessed and results from other studies suggest effects on motor impairment. In addition, many studies focused analyses on latency of response rather than on acquisition of learning.

^3^ Assessing publication bias through typical approaches was limited, such as through funnel plots, publication of conference abstracts in the peer-review literature, or other means. With respect to conflict of interest, authors report “no conflict of interest,” it was not reported, or research was supported by academia or government.

^4^ No upgrading was considered for dose response and magnitude of effect because of concern for risk of bias and indirectness (confounding effects of impaired motor function on the learning and memory function tests).

NOTE: OHAT includes consideration of consistency of response across different animal model systems as an upgrade factor when evaluating the quality of the evidence, but consistency of response was not a major consideration in this review because most studies were on rodents, primarily rats.