# Methods

The systematic review was conducted based on guidance outlined in the Office of Health Assessment and Translation (OHAT) Handbook for Conducting a Literature-Based Health Assessment (NTP 2015a). Methods are summarized below and presented in more detail in the study protocol available at https://hawcproject.org/assessment/126/.

## Development of Research Question

A PECO statement ([underlined: P]opulation, [underlined: E]xposure, [underlined: C]omparator, [underlined: O]utcome) was developed to address and understand potential effects of fluoride on neurobehavioral measures in animal models, especially related to learning and memory (Table 2).

Table 2 PECO (Populations, Exposures, Comparators, Outcomes) Statement

PECO | Evidence
[underlined: P]opulation | Non-human mammalian animal species (whole organism) of all ages
[underlined: E]xposure | Fluoride at any concentration; relevant forms are those used as additives for water fluoridation: [underlined: fluorosilicic acid] (also called hydrofluorosilicate; CASRN 16961-83-4) [underlined: sodium hexafluorosilicate] (also called disodium [underlined: hexafluorosilicate] or sodium fluorosilicate; 16893-85-9) [underlined: sodium fluoride] (CASRN 7681-49-4) other forms that readily [underlined: dissociate] into free fluoride ions (e.g., potassium fluoride, calcium fluoride, ammonium fluoride)
[underlined: C]omparator | Animals exposed to vehicle-only treatment
[underlined: O]utcomes | Any neurobehavioral outcome [underlined: Primary outcomes]: learning and memory [underlined: Secondary outcomes]: motor and sensory function, and other aspects of behavior that do not fall under learning and memory (e.g., anxiety, territorial aggression)

## Literature Search Strategies

### Searching Electronic Databases

Systematic search strategies were developed to identify all relevant published evidence on the health effects of water fluoridation by using index terms and text words based on key elements of the research question. Nine electronic databases^4^ initially were searched on January 7, 2015, and the search was updated on January 14, 2016, unless noted otherwise:

4 NLM’s Toxline database was not included in the search because recent changes have resulted in significant reductions in search functionality that limits running the search strings for this topic. In addition, the other databases are very likely to identify relevant published and peer-reviewed animal studies.

- BIOSIS (Thomson Reuters – searched 2/18/2015)
- EMBASE (Elsevier)
- European Chemicals Agency (ECHA) Registration dossiers (“REACH”) (http://echa.europa.eu/web/guest/information-on-chemicals/registered-substances) database (searched 3/24–27/2015)
- Organization for Economic Co-operation and Development (OECD) Existing Chemicals (http://www.echemportal.org/echemportal/participant/participantinfo.action?participantID=1) Screening Information Data Sets (SIDS) (http://www.echemportal.org/echemportal/participant/participantinfo.action?participantID=1) database (searched 2/18/2015)
- PsycINFO (APA [American Psychological Association] PsycNet)
- PubMed (National Library of Medicine [NLM])
- Scopus (Elsevier)
- USEPA HPV Challenge Program Robust Summaries and Test Plans (http://cfpub.epa.gov/hpv-s/) database ([High Production Volume] searched 3/23/2015)
- Web of Science (Thomson Reuters; Web of Science indexes the journal, Fluoride)

No publication date or language restrictions were applied. Full details of the search strategy for each database are presented in Appendix A.

### Searching Other Resources

The reference lists of included studies, records that do not contain original data (i.e., reviews, editorials, or commentaries), and the Fluoride Action Network website (“Fluoride affects learning and memory in animals” at http://fluoridealert.org/studies/brain02/) were searched for additional relevant publications.

## Selection Criteria for the Evidence

Studies were screened for inclusion using a structured form in DistillerSR (Evidence Partners; https://distillercer.com/products/distillersr-systematic-review-software/). Two members of the evaluation design team independently conducted a title and abstract screen of the search results to identify studies that met the eligibility criteria. Studies that were not excluded based on the title and abstract advanced to full-text review. For citations with no abstract, articles were screened based on all or some of the following: title relevance (title should indicate clear relevance), page numbers (articles two pages in length or less were assumed conference reports, editorials, or letters), and PubMed MeSH (Medical Subject Headings).

Full-text copies of potentially relevant articles were independently assessed by two reviewers to identify studies that satisfied the inclusion and exclusion criteria. Discrepant screening results were resolved by discussion. Assessment of eligibility status of non-English studies was facilitated by native-language speakers at ICF International or National Institute of Environmental Health Sciences (NIEHS).

To be eligible for inclusion, studies had to comply with the criteria specified by the PECO statement (Table 2). Studies that did not meet the PECO criteria were excluded. In addition, the following exclusion criteria were applied:

- Studies did not contain original data, such as reviews, editorials, or commentaries.
- Studies were not peer reviewed (e.g., conference abstracts, technical reports, theses/dissertations, working papers from research groups or committees, white papers).

## Data Collection and Presentation

### Data Extraction

Data were extracted from individual studies by members of the evaluation team using DRAGON (Dose Response Analytical Generator and Organizational Network) and Health Assessment Workspace Collaborative (HAWC)^5^ software. Data extraction elements collected from animal studies are listed in Appendix B Information on concentrations of fluoride measured in brain, blood, urine, or bone also was summarized when available. One member of the evaluation team extracted the data, which a second member checked. Missing data from individual studies were not sought. Extracted data were warehoused using HAWC.

5 ICF International. 2014. From Systematic Review to Assessment Development: Managing Big (and Small) Datasets with DRAGON. http://www.icfi.com/insights/products-and-tools/dragon-online-tool-systematic-review. Health Assessment Workspace Collaborative (HAWC): A Modular Web-based Interface to Facilitate Development of Human Health Assessments of Chemicals. https://hawcproject.org/portal/.

### Quality Assessment of Individual Studies

Risk of bias ratings for individual studies were assessed using the OHAT tool (NTP 2015b) (Table 3). Two raters assessed the studies, answering nine risk of bias questions following guidance outlined in OHAT’s risk of bias documentation (NTP 2015b). After one reviewer independently determined risk of bias across all questions, a second person went through and agreed or disagreed with the ratings. Differences in ratings were discussed and resolved. Authors were queried to obtain missing information, and responses received were used to evaluate risk of bias. Information that was not reported was assumed not conducted (e.g., randomization, blinding), resulting in an assessment of “probably high” risk of bias.

Table 3 OHAT Risk of Bias Questions for Evaluating Experimental Animal Studies

OHAT Risk of Bias Questions for Evaluating Experimental Animal Studies
Questions
Selection Bias
1. Was administered dose or exposure level adequately randomized?
2. Was allocation to study groups adequately concealed?
Performance Bias
3. Were experimental conditions identical across study groups?
4. Were the research personnel and human subjects blinded to the study group during the study?
Attrition/Exclusion Bias
5. Were outcome data complete with respect to attrition or exclusion from analysis?
Detection Bias
6. Can we be confident in the exposure characterization?
7. Can we be confident in the outcome assessment?
Selective Reporting Bias
8. Were all measured outcomes reported?
Other Sources of Bias
9. Were there no other potential threats to internal validity (e.g., statistical methods were appropriate)?
Response Options
Definitely Low risk of bias: There is direct evidence of low risk of bias practices. | ++
Probably Low risk of bias: There is indirect evidence of low risk of bias practices OR it is deemed that deviations from low risk of bias practices for these criteria during the study would not appreciably bias results. | +
Probably High risk of bias: There is indirect evidence of high risk of bias practices OR there is insufficient information (e.g., not reported or “NR”) provided about relevant risk of bias practices. | –/NR
Definitely High risk of bias: There is direct evidence of high risk of bias practices. | –

#### Critical Risk of Bias Domains

Randomization to treatment group, blinding during neurobehavioral outcome assessment, adequate characterization of the administered chemical, and controlling for litter effects in developmental studies were considered key factors in determining whether a study had an overall very serious risk of bias concern, referred to as a “tier 3” study in the OHAT Handbook (NTP 2015a). Studies considered as having “probably high” or “definitely high” risk of bias in several of these domains were classified as tier 3 studies and excluded from the main analysis, although the impact of excluding the studies was considered. Studies also may be considered tier 3 due to a combination of concern for risk of bias in a critical domain(s) and very poor reporting quality (e.g., not reporting the number of animals treated).

Randomization and blinding during outcome assessment were considered especially critical factors for risk of bias assessment because of empirical support that failure to implement these factors can bias results away from the null toward larger effects (Higgins and Green 2011; Krauth et al. 2013). The extent of empirical support documenting these biases in animal studies is better documented compared to other risk of bias factors, for example, blinding during allocation to study groups or during the course of the study (NTP 2015b). In addition, concern for lack of blinding during allocation or the conduct of the study can be attenuated if blinding was implemented at outcome assessment. For these reasons, blinding at outcome assessment was weighed more heavily during risk of bias assessment than blinding during allocation concealment or during the course of the study. In neurobehavioral studies, concern for lack of blinding at outcome assessment is attenuated if behavioral parameters are measured by an automated, computer-driven system.

Adequate characterization of the test compound is necessary to evaluate the purity and stability of the chemical exposure. Independent verification of purity would be considered best practice because the identity and purity as listed on the bottle can be inaccurate. In NTP’s experience, about 3% of chemicals purchased are the wrong chemical, and the inaccuracy rate of chemical labeling increases to 10% if inaccurate reporting of purity is included (unpublished, personal communication Brad Collins, NTP chemist). Impurities also might be more toxic than the compound of interest.

Adequate control for litter effects when littermates are used in an experiment is considered essential in developmental studies. In 2000, NTP co-sponsored a workshop with EPA, “Low Dose Endocrine Disruptors Peer Review.” As part of the peer review, a group of statisticians reanalyzed several “low” dose studies (Haseman et al. 2001). Based on studies that used littermates, they determined that litter or dam effects were generally present such that pups within a litter were found to respond more similarly than pups from different litters. The overall conclusion was “[f]ailure to adjust for litter effects (e.g., to regard littermates as independent observations and thus the individual pup as the experimental unit) can greatly exaggerate the statistical significance of experimental findings.”

### Evidence Synthesis

#### Endpoint Grouping

Neurobehavioral endpoints were categorized by nature of behavioral domains using the framework below (Table 4). Findings were synthesized at the test/endpoint level to reach conclusions about potential impacts of fluoride at the domain level (e.g., learning and memory, motor, anxiety). The priority domain in this report is learning and memory.

Table 4 Framework for Neurobehavioral Groupings

General Domain | Example Test and Endpoints
Learning and Memory | Maze tests (Morris water maze, T-maze, Y-maze); exploration (novel object recognition, mini-holeboard, activity cage); active and passive avoidance (step-down test, shuttle box); operant behavior
Motor and Sensory Function | Locomotor activity (open field, activity cage); movement coordination (akinesia/catalepsy, plank walking, rotarod, slanted surface, swim test); reflex (auditory startle, negative geotaxis, pain response: tail immersion and Von Frey hair test); developmental motor sensory landmarks (cliff avoidance, surface righting, pivoting/orienting reflex)
Depression | Forced swim; tail suspension test
Anxiety | Elevated plus maze
Other | Grooming; urination/defecation; sexual behavior; territorial behavior

#### Considerations for Pursuing a Narrative or Quantitative Evidence Synthesis

Heterogeneity within the available evidence was considered when determining whether to calculate an overall estimate of effect (meta-analysis) of fluoride effects on learning and memory. The principal characteristics evaluated for heterogeneity across eligible studies include the following:

- Animal model used (species, strain, sex, genetic background)
- Age of animals (at start of treatment, mating, pregnancy status)
- Dose levels, frequency of treatment, timing, duration, and exposure route
- Behavioral measurements and methodology
- Type of data (e.g., continuous, dichotomous), statistics presented in paper, ability to access raw data
- Concern for risk of bias

#### Standardizing Results from Behavioral Tests and Dose Levels

Results from behavioral tests were transformed, when possible, to a common metric of percent change from control response to help assess dissimilar but related outcomes measured with different scales. In this project, percent control response was used as the common metric because it is recommended for assessing dissimilar but related outcomes measured with different scales (Vesterinen et al. 2014). Percent control group calculations were based on sample size, means, and standard deviation or standard error values presented in the studies.

For studies in which experimental animals were dosed with sodium fluoride (NaF) or other forms of dissociable fluoride, dose levels were converted to fluoride equivalents (F), for example, 100 ppm NaF = 45.3 ppm (mg/L) fluoride. In studies where F was administered directly (often reported simply as “fluoride”), no such conversions were conducted. Fluoride dose levels were standardized to mg/kg-d and ppm (mg/L). Conversions were made using water consumption rates and body weights for rats and mice reported in the EPA dosimetry (US EPA 1988; 1994). In each case, the “subchronic” values were chosen because this period fit the maternal or single-generation dosing periods in most studies. The strain-specific and sex-specific values were used when available; for strains that were not available, the “other” values were used. For the few studies in which dosing was through the feed, conversion was first made from food ppm to mg/kg-d. Then, the “effective water concentration” was estimated by multiplying the converted dietary dose by body weight and dividing by water consumption rate. The uncertainty in these estimates should be considered higher than in water consumption studies.

Unless otherwise reported by study authors, the fluoride background level was assumed 0 ppm (0 mg/kg-d). Dose levels provided in studies are presented here as mg/kg-d and ppm as available. Dose conversions were made using US EPA (1988; 1994) default food or water consumption rates and body weights (using subchronic age and experiment duration) for the species/strain and sex of the animal of interest. Dose levels in mg/kg-d can vary for a given ppm across different studies if the studies use different species/strain or sex of animals, or both, that are assumed to have different food or water consumption rates.

### Assessment of Confidence in the Body of Evidence

The quality of evidence for learning and memory^6^ was evaluated using the GRADE system for rating the confidence in the body of evidence (Guyatt et al. 2011a; NTP 2015a). Under the GRADE system, overall confidence in the body of evidence for an outcome is categorized as high, moderate, low, or very low. Like experimental human studies (randomized clinical trials), evidence from animal studies is initially graded as high quality by OHAT. Next, a series of adjustments (“downgrades” or “upgrades”) (Table 5) were made to the initial ranking based on the characteristics of the studies constituting the body of evidence after considering factors. The factors included risk of bias across studies, unexplained inconsistency, indirectness, imprecision, publication bias, effect magnitude, dose response, and consistency across different model systems and study designs (Figure 1, see also NTP (2015a) for additional detail). Studies conducted in mammalian model systems are assumed relevant for humans (i.e., not downgraded for indirectness) unless compelling evidence to the contrary exists.

6 Although level-of-evidence conclusions focused on learning and memory, studies evaluating other aspects of behavior were identified, and data were extracted and assessed for risk of bias (Appendix D through Appendix R).

Table 5 Key Factors When Considering Whether to Downgrade or Upgrade

Downgrade Factors
Risk of Bias | Risk of bias across all domains but with priority consideration for these critical factors: Randomization, blinding at outcome assessment, exposure characterization (reporting source, purity, internal dose level), control for litter effects in developmental exposure studies.
Inconsistency | Presence of unexplained inconsistency in studies of similar design. Compared to clinical human data, differences between experimental animal studies could be larger due to factors such as use of different strains (which are often inbred to minimize variability), different exposure or treatment paradigms, and differences in handling or laboratory conditions (Vesterinen et al. 2014).
Indirectness | [underlined: Within the animal model]: Directness of the measure as an indicator of learning and memory, for example, ability to rule out impaired motor or sensory functions that might impact ability of animals to perform the learning and memory tests. Also consider route of administration; oral is considered most relevant for fluoride. [underlined: Animal (rodent) to human extrapolation]: In vivo mammalian model systems have demonstrated utility for examining autonomic, sensory, and motor system functioning as they relate to human health. Although human cognitive function is not easily assessed in such systems, aspects of learning and memory can be evaluated as based on learning theory that translates across species (Crawley 2007). Some neurobehavioral measures, however, have not been demonstrated to translate readily across species (social behaviors, aggression, risky behaviors) and others (e.g., verbal learning/performance, gender preferences) cannot be evaluated adequately in a nonhuman mammalian model system.
Imprecision | Confidence in quantitative measures such as effect sizes, identification of no observed effect level (NOEL) or lowest observed effect level (LOEL) doses, or parameters for benchmark dose analysis. Typically, 95% confidence intervals are used as the primary method to assess imprecision (Guyatt et al. 2011b). OHAT also considers whether studies are adequately powered when considering whether to downgrade.
Publication Bias | Downgrade if “strongly detected.” Publication bias is difficult to assess (Guyatt et al. 2011c), especially when multiple endpoints related to the primary outcome are reported in the same study, few studies are available, and papers lack reporting on funding and conflict of interest. Analytical tools, such as funnel plots or trim-and-fill approaches, can be useful to assess publication bias but also have substantial limitations and should be interpreted with caution (Guyatt et al. 2011c).
Upgrade Factors
Large Magnitude of Effect | Determining whether the magnitude of the effect is large includes consideration of factors such as the effect being measured and the dose range used. No upgrade considered if serious concern for risk of bias is present.
Dose Response | Patterns of dose response are evaluated within and across studies when considering whether to upgrade for evidence of dose response. No upgrade considered if serious concern for risk of bias.
Consistency across Animal Models or Species | An upgrade may be considered for consistent results reported in multiple experimental animal models or species.

Figure 1

Assessing Confidence in the Body of Evidence (“Quality of Evidence”)

### Preparation of Level-of-evidence Conclusions

Confidence levels in the body of evidence conclusions from Figure 1 were translated into statements of health effects from animal studies according to one of four statements: (1) High, (2) Moderate, (3) Low, or (4) Inadequate (Figure 2). The descriptor “evidence of no health effect” is used to indicate confidence that the substance is not associated with a health effect as detected by neurobehavioral outcomes. Because of the inherent difficulty in proving a negative, the conclusion “evidence of no health effect” is reached only when confidence in the body of evidence is high.

Figure 2

Translate Confidence Ratings into Evidence of Health Effect Conclusions from Animal Studies