# Introduction

## Sources of Exposure

In 2010, the US Environmental Protection Agency (EPA) conducted a relative source contribution analysis of fluoride. Sources include drinking water, foods, beverages, dental products (toothpaste, mouth rinses), supplements, industrial emissions, pharmaceuticals, and pesticides (e.g., cryolite, sulfuryl fluoride). Soil ingestion is another source of exposure in young children (US EPA 2010b). The major contributors to exposure are drinking water, beverages, food, and toothpaste. The relative source contribution from drinking water intake was 40–60% after the age of 1 year and 70% in children less than 1 year old.

Table 1 Representative Values for Fluoride Intakes Used in Calculation of the Relative Source Contribution from Drinking Water

Age Group (years) | DWI^a^ (mg/d) | BI (mg/d) | FI (mg/d) | TI (mg/d) | SuF (mg/d) | SI (mg/d) | Total (mg/d) | RSC (%)
0.5–<1 | 0.84 | – | 0.25^b^ | 0.07 | 0.03 | 0.02 | 1.2 | 70
1–<4 | 0.63 | 0.36 | 0.16 | 0.34 | 0.05 | 0.04 | 1.58 | 40
4–<7 | 0.82 | 0.54 | 0.35 | 0.22 | 0.06 | 0.04 | 2.03 | 40
7–<11 | 0.86 | 0.60 | 0.41 | 0.18 | 0.07 | 0.04 | 2.16 | 40
11–14 | 1.23 | 0.38 | 0.47 | 0.20 | 0.09 | 0.04 | 2.41 | 51
>14 | 1.74^b^ | 0.59 | 0.38 | 0.10^c^ | 0.08 | 0.02 | 2.91 | 60

From Table 7-2 (US EPA 2010b).

^a^ Consumers only; 90th percentile intake except for >14 years of age. The >14-year value is based on the Office of Water policy of 2 L/d.

^b^ Includes foods, fluoride in powdered formula, and fruit juices; no allocation for other beverages.

^c^ Assumed. 50% of the 11- to 14-year-old age group. DWI = drinking water intake; BI = beverage intake; FI = food intake (solid foods); TI = toothpaste intake; SuF = sulfuryl fluoride intake; SI = soil intake; RSC = relative source contribution.

EPA has proposed a reference dose (RfD) of 0.08 mg/kg-d for protection against pitting of tooth enamel (severe dental fluorosis), and this value also is considered protective against fractures and skeletal effects in adults (US EPA 2010a).

## Use of Fluoride to Prevent Tooth Decay

Fluoride from community water fluoridation, mouth rinses, gels, and toothpastes is intended to prevent dental caries primarily through topical remineralization of tooth surfaces. Community water fluoridation and fluoride toothpaste are the most common sources of non-dietary fluoride in the United States (US DHHS 2015). Because fluorine is the 13th most abundant element in Earth’s crust, fluoride also naturally occurs in water and is present in many non-fluoridated water systems.

Although other fluoride-containing products and sources are available (e.g., mouth rinses, dietary supplements, professionally applied fluoride compounds), community water fluoridation has been identified as the most cost-effective method for delivering fluoride to all members of the community regardless of age, educational attainment, or income level. Consuming fluoridated water and beverages and foods prepared or processed with fluoridated water throughout the day maintains a low concentration of fluoride in saliva and plaque, which enhances remineralization (US DHHS 2015). Community water fluoridation to minimize the occurrence and severity of tooth decay, which began in 1945, had reached 67% of the US population by 2012. About 25 countries practice community water fluoridation (Iheozor-Ejiofor et al. 2015), and many more provide fluoride through other means such as salt. In 2012, an estimated 200 million people in the United States were served by 12,341 community water systems that added fluoride to water or purchased water with added fluoride from other systems (US DHHS 2015).

The US Public Health Service (PHS) first recommended communities add fluoride to drinking water in 1962. PHS guidance is advisory, not regulatory, which means that although PHS recommends community water fluoridation as an effective public health intervention, state and local governments decide whether to fluoridate water systems. For community water systems that add fluoride, PHS currently recommends a fluoride concentration of 0.7 milligrams/liter (mg/L, ppm).^1^ This recommended level provides the best balance of protection from dental caries, while limiting the risk of dental fluorosis. Dental fluorosis is a condition marked by changes in the appearance of tooth enamel most commonly appearing as lacy white markings (US DHHS 2015). Dental fluorosis can result when children regularly consume fluoride from birth through 8 years of age—the time when their permanent teeth (with the exception of the third molars) are developing.

1 For many years, most fluoridated community water systems used fluoride concentrations ranging from 0.8 to 1.2 mg/L (US DHHS 2015).

Under the Safe Drinking Water Act, EPA sets standards for drinking water quality. Currently, the enforceable fluoride standard is set at 4.0 mg/L to protect consumers from exposure to drinking water sources with naturally high occurrence of fluoride against severe skeletal fluorosis (a condition caused by excessive fluoride intake over a long period that, in advanced stages, can cause pain, crippling damage to bones and joints, or both). EPA also has a secondary drinking water standard of 2.0 mg/L to protect against moderate to severe dental fluorosis. This secondary standard is not enforceable but requires water systems to notify the public. EPA is currently reviewing the drinking water standards for fluoride (US EPA 2013).

## Concerns for Potential Fluoride Toxicity

The most commonly cited health concerns about fluoride and water fluoridation focus on bone fractures and skeletal fluorosis, intelligence quotient (IQ) and other neurological effects, cancer, and endocrine disruption. Effects on neurological function, endocrine functions (thyroid, parathyroid, pineal), metabolism (glucose), and carcinogenicity were assessed in the 2006 National Research Council (NRC) report, Fluoride in Drinking Water: A Scientific Review of EPA’s Standards (NRC 2006). The review considered adverse effects of water fluoride, focusing on concentrations of 2–4 mg/L,^2^ a range higher than the current recommendation for community water fluoridation (0.7 mg/L). At levels below 4.0 mg/L, NRC found no evidence substantial enough to support negative health effects other than severe dental fluorosis. The conclusions from the NRC review were the primary source of information for the potential hazard summary in a 2015 report by the US Department of Health and Human Services (DHHS), Federal Panel on Community Water Fluoridation. The NRC report noted several challenges to evaluating the literature, including deficiencies in reporting quality; consideration of all sources of fluoride exposure; consideration of potential confounding; selection of appropriate control subject populations in epidemiology studies; demonstrated clinical significance of endocrine effects; and the biological relationship between histological, biochemical, and molecular alterations with behavioral effects. Regarding neurotoxicity and neurobehavioral effects, the main conclusions in the 2006 NRC report are:

2 EPA’s maximum contaminant level goal (MCLG) for fluoride is 4 mg/L and secondary maximum contaminant level (SMCL) is 2 mg/L. MCLGs establish an exposure guideline to prevent adverse health effects in the general population, and SMCLs are intended to reduce the occurrence of adverse cosmetic consequences from exposure to fluoride. Both the MCLG and the SMCL are nonenforceable guidelines (NRC 2006).

“Animal and human studies of fluoride have been published reporting adverse cognitive and behavioral effects. A few epidemiologic studies of Chinese populations have reported IQ deficits in children exposed to fluoride at 2.5 to 4 mg/L in drinking water. Although the studies lacked sufficient detail for the committee to fully assess their quality and relevance to U.S. populations, the consistency of the results appears significant enough to warrant additional research on the effects of fluoride on intelligence.” [p. 8] (NRC 2006)

“A few animal studies have reported alterations in the behavior of rodents after treatment with fluoride, but the committee did not find the changes to be substantial in magnitude. More compelling were studies on molecular, cellular, and anatomical changes in the nervous system found after fluoride exposure, suggesting that functional changes could occur. These changes might be subtle or seen only under certain physiological or environmental conditions. More research is needed to clarify the effect of fluoride on brain chemistry and function.” [p. 8] (NRC 2006)

Since release of the 2006 NRC report, approximately 10 epidemiological studies of children’s IQ have been published. A 2015 systematic analysis of the human literature conducted for the Republic of Ireland’s Department of Health (Sutton et al. 2015) reviewed the new literature and concluded no evidence of an association with lowered IQ was apparent in studies of community water fluoridation. The authors based this conclusion primarily on an analysis of a prospective cohort study conducted in New Zealand (Broadbent et al. 2015). For fluoride-endemic areas, there was a strong suggestion that high levels of naturally occurring fluoride in water (>1.5 ppm) could be associated with negative health effects, including lowering of IQ. Overall, these studies were considered low quality, as they did not fully account for known confounding factors with regard to IQ (e.g., nutritional status, socioeconomic status), nor other potential influencing factors (e.g., iodine deficiency, chemical contaminants in the ground water such as arsenic and lead). The conclusions of Sutton et al. (2015) are consistent with findings of a 2012 meta-analysis of 27 epidemiology studies that supported the possibility of an adverse effect of “high” fluoride exposure^3^ on children’s neurodevelopment, specifically for lowered IQ (Choi et al. 2012). The Choi et al. meta-analysis, however, also identified study quality limitations, primarily related to reporting quality, that limited the strength of the conclusions (Choi et al. 2012). More than 35 experimental animal studies evaluating the neurobehavioral effects of fluoride have been published since release of the 2006 NRC report. A systematic review of experimental studies that focuses on the effects of fluoride on learning and memory would help interpret the human literature on IQ and identify key research/data gaps for additional study.

3 “High” was defined based on drinking water concentration, evidence of fluorosis, exposure related to coal-burning activities, and urine levels.

For cancer and endocrine disruption, the National Toxicology Program (NTP) is analyzing the amount of evidence available and the merit of pursuing systematic reviews given factors such as the extent of new research published since previous evaluations and whether these new reports address or correct the deficiencies noted in the literature (OEHHA 2011; NRC 2006; SCHER 2011).

## Objectives and Research Strategy

The overall objective of this evaluation is to undertake a systematic review of the existing animal studies to develop NTP level-of-evidence conclusions (NTP 2015a) about whether fluoride exposure is associated with impairments in learning and memory.

### Research Strategy

- Identify literature reporting the effects of exposure to fluoride and neurobehavioral outcomes in experimental animal studies utilizing mammalian species (whole organism).
- Extract data on neurobehavioral outcomes from identified studies. Primary outcomes are learning and memory, but other behavioral measures are summarized (e.g., “anxiety,” motor function).
- Assess the internal validity (“risk of bias”) of individual studies.
- Summarize the extent of evidence available.
- Synthesize the evidence, and perform quantitative meta-analyses if appropriate, and evaluate sources of heterogeneity.
- Rate confidence in the body of evidence for effects on learning and memory according to one of four statements: (1) High, (2) Moderate, (3) Low, or (4) Very Low/No Evidence Available.
- Translate confidence ratings into level-of-evidence for effects on learning and memory according to one of four statements: (1) High, (2) Moderate, (3) Low, or (4) Inadequate.
- Describe limitations of the evidence base, limitations of the systematic review, and findings in the context of human exposure levels.
- Identify data gaps and key research needs.