# Appendix V Background Fluoride Levels in Drinking Water and Diet

Table V-1 Background Fluoride Levels in Drinking Water and Diet

Reference | Route of Administration | Vehicle Control | Background Fluoride in Drinking Water | Background Fluoride in Feed
Balaji et al. (2015) | Drinking water | Nonfluoridated water | NR | NR
Balayssac et al. (2002) | Drinking water | Deionized water | NR | 14 ppm
Banji et al. (2013) | Drinking water | Deionized water | NR | NR
Bǎran-Poesina et al. (2013) | Drinking water | Distilled water | NR | NR
Bartos et al. (2015) | Drinking water | Drinking water | NR | NR
Basha et al. (2011) | Drinking water | Tap water (<1 ppm F) | 1 ppm | NR
Basha and Sujitha (2012) | Drinking water | Tap water | NR | NR
Bataineh and Nusier (2006) | Drinking water | Tap water (NaF = 1.2 ppm) | 0.54 ppm | NR
Bera et al. (2007) | Gavage | Deionized water | NR | NR
Bhatnagar et al. (2002) | Drinking water | Deionized, defluoridated water | NR | NR
Chen and Geng (2011) | Drinking water | Distilled water | NR | NR
Chioca et al. (2008) | Drinking water | Drinking water (NaF = 1.54 ppm) | 0.697 ppm | NR
Dong et al. (2015c) | Drinking water | Drinking water (<0.5 ppm F) | <0.5 ppm | 6.2 mg/kg
Dong et al. (2015b) | Drinking water | Drinking water (<0.5 ppm F) | <0.5 ppm | 6.2 mg/kg
Dong et al. (2015a) | Drinking water | Drinking water (<0.5 ppm F) | <0.5 ppm | 6.2 mg/kg
Ekambaram and Paul (2001) | Drinking water | Drinking water (0.2 ppm F) | 0.2 ppm | NR
Ekambaram and Paul (2002) | Drinking water | Drinking water (0.2 ppm F) | 0.2 ppm | NR
Ekambaram and Paul (2003) | Drinking water | Tap water | NR | NR
El-lethey et al. (2010) | Drinking water | Distilled water | NR | NR
El-lethey et al. (2011) | Drinking water | Distilled water | NR | NR
El-lethey and Shaheed (2011) | Drinking water | Distilled water | NR | NR
El-lethey and Kamel (2011) | Drinking water | Distilled water | NR | NR
Elliott (1967) | Dietary | Well below 1 ppm in drinking water | <1 ppm | Fluorine content 0.002% in feed
Flace et al. (2010) | Gavage | Deionized water | NR | NR
Gao et al. (2008a) | Drinking water | Drinking water (<0.5 ppm F) | <0.5 ppm | NR
Gao et al. (2008b) | Drinking water | Drinking water (<1 ppm F) | <1.0 ppm | NR
Gao et al. (2009a) | Drinking water | Drinking water (<0.5 ppm NaF) | <0.23 ppm | NR
Gao et al. (2009b) | Gavage | Deionized water | NR | NR
Gopal et al. (2006) | Gavage | NR | NR | NR
Gui et al. (2010) | Dietary | Tap water (0.5 ppm F) | 0.5 ppm | 6.2 mg/kg
Han et al. (2014) | Drinking water | Distilled water | NR | NR
Hong et al. (2005) | Drinking water | Deionized water | NR | 25.57 mg/kg
Jain et al. (2015) | Drinking water | NR | NR | NR
Jetti et al. (2016) | Drinking water | Tap water (0.5 ppm F) | 0.5 ppm | NR
Jiang et al. (2014a) | Drinking water | Tap water (0.34 mg/L F) | 0.34 ppm | NR
Jiang et al. (2014b) | Drinking water | Tap water | NR | NR
Kivrak (2012) | Drinking water | Drinking water (0.3 ppm F) | 0.3 ppm | NR
Li et al. (2015) | Drinking water | Distilled water | NR | NR
Liu (1989) | Drinking water | Distilled water | NR | 2.9 ppm
Liu et al. (2009) | Drinking water | Tap water (<0.5 ppm NaF) | 0.23 ppm | NR
Liu et al. (2010) | Drinking water | Drinking water (<0.5 ppm NaF) | 0.23 ppm | NR
Liu et al. (2011) | Drinking water | Tap water (<0.5 ppm F) | 0.5 ppm | NR
Liu et al. (2014) | Drinking water | Distilled water | NR | NR
Ma et al. (2015) | Drinking water | Distilled water | NR | NR
Mullenix et al. (1995) | Drinking water | Deionized water | NR | <10 ppm
Niu et al. (2008) | Drinking water | Double distilled water | NR | NR
Niu et al. (2009) | Drinking water | Double distilled water | NR | NR
Niu et al. (2014) | Drinking water | Double distilled water | NR | NR
Paul et al. (1998) | Gavage | Tap water | NR | NR
Pereira et al. (2011) | Drinking water | Tap water (0.7 ppm F) | 0.7 ppm | NR
Raghu et al. (2013) | Drinking water | Tap water (0.5 ppm F) | 0.5 ppm | NR
Reddy and Karnati (2015) | Intraperitoneal | NR | NR | NR
Rumiantsev et al. (1988) | Gavage | NR | NR | NR
Sarkozi et al. (2015) | Gavage | Distilled water | NR | NR
Shen et al. (2004) | Drinking water | Tap water | NR | NR
Sun et al. (2008) | Drinking water | Tap water | NR | NR
Wang et al. (2004) | Drinking water | Drinking water (<0.6 ppm F) | 0.6 ppm | 25.57 mg/kg
Wang et al. (2006) | Drinking water | Free water | NR | NR
Wei et al. (2014) | Drinking water | Tap water (<1 ppm NaF) | 0.45 ppm | <5 mg/kg
Whitford et al. (2009) | Drinking water | Distilled drinking water | NR | <0.01 mg/kg-d
Wu et al. (2006) | Drinking water | Distilled water | NR | NR
Wu et al. (2008) | Drinking water | Tap water (0.6 ppm F) | 0.6 ppm | NR
Xu et al. (2001) | Drinking water | Distilled fluoride-free water | NR | NR
Zhang et al. (2013) | Gavage | Drinking water (<0.07 ppm NaF) | 0.07 ppm | NR
Zhang et al. (1999) | Drinking water | Distilled water | NR | NR
Zhang et al. (2001) | Drinking water | Deionized water | NR | NR
Zhang et al. (2009) | Drinking water | Fluoride-free water | NR | Fluoride-free
Zhu et al. (2012) | Drinking water | Distilled water | NR | NR