# Appendix U Pharmacokinetics and Concentrations of Fluoride Measured in Tissue, Blood, Urine, or Bone

The predominant route and source of human exposure to fluoride is by oral ingestion of drinking water (either with naturally occurring or added fluoride), food, and dental products containing fluorides (US DHHS 2015; US EPA 2010b). Fluoride from water and dental products is in the form of fluoride ion, released in solution from water-soluble fluorides such as sodium fluoride, hydrogen fluoride, fluorosilicic acid, or sodium monofluorophosphate (Ekstrand et al. 1978; Spak et al. 1982). Fluoride compounds with low water solubility such as calcium fluoride, magnesium fluoride, or aluminum fluoride are poorly absorbed (IPCS 2002). The pharmacokinetics of fluoride are driven primarily by pH and storage in bone (NRC 2006). The acidic environment of the stomach promotes the conversion of fluoride ion to hydrogen fluoride, which is rapidly absorbed by passive diffusion from the stomach and small intestine (Whitford and Pashley 1984). Approximately 70–90% of ingested fluoride is absorbed in the alimentary tract and, for very soluble forms such as sodium fluoride, absorption is almost 100% (NRC 2006). Peak plasma concentrations are reached within 30 min (IPCS 2002). Calcified tissues such as bone and teeth readily incorporate fluoride (NRC 2006).

When taken with food, the rate of fluoride absorption from the gut and overall bioavailability are both lowered, thought due to binding of fluoride ions to calcium or other food constituents (Ekstrand and Ehrnebo 1979; Shulman and Vallejo 1990; Trautner and Einwag 1989). In healthy young adults, blood levels of fluoride, when expressed as micrograms per liter, approximate the consumed water concentration of fluoride expressed as mg/L (NRC 1993). Fluoride is cleared from plasma primarily through uptake by bone and excretion in urine, and clearance by these two routes is approximately equal in healthy adult humans (Whitford 1996). Clearance of fluoride from plasma occurs with a half-life estimated between 3 and 10 hours, depends on dose, and is affected by renal function and ongoing bone accretion and dissolution (Waterhouse et al. 1980). A significant amount of fluoride is cleared from blood by deposition into mineralized tissues. In animals and humans, approximately 99% of the body burden of fluoride is in bones and teeth (Hamilton 1992; Kaminsky et al. 1990). Fluoride is incorporated into the crystal lattice structure of mineralized tissues in the form of partially fluoridated hydroxyapatite (WHO 1994).

In infants and children, fluoride intake varies with age and diet, and relative clearance from plasma into mineralized tissues is extensive; clearance in children is larger compared to adults because of their growing skeletal system (Ekstrand et al. 1994; Ophaug et al. 1980). The features of developing versus mature bone provide more surface area for reaction with fluoride (Whitford 1996). In the elderly, blood fluoride levels can be elevated because of reduced capacity of bone to absorb fluoride, diminishing bone mass, and impaired renal function (IPCS 2002). Fluoride freely crosses the placenta, although concentrations in breast milk are lower than in plasma (Shen and Taves 1974). Whether consumption of fluoridated versus nonfluoridated water by the mother materially affects breast-milk fluoride concentrations is not yet settled (Dabeka et al. 1986; Ekstrand et al. 1981). Formula-fed infants are exposed to higher levels of fluoride than breast-fed infants, particularly when formula is reconstituted with fluoridated water (IPCS 2002). The blood-brain barrier is thought to reduce fluoride transfer (Whitford 1996).

Rats appear to require higher chronic exposure than humans to achieve the same plasma and bone fluoride concentrations, with one estimate of five times higher water concentrations required to achieve the same plasma concentration (Dunipace et al. 1995). With respect to bone, one study estimated that “humans incorporate fluoride ~18 times more readily than rats when the rats are on a normal calcium diet” (Turner et al. 1995). Several studies in rodents cited in this document have measured serum or plasma levels of fluoride following exposures to various elevated levels in drinking water (Table U-1). These studies have reported relationships between fluoride concentrations in drinking water and plasma/serum ranging from approximately 70–8000 times higher levels in water than were measured in plasma/serum (Table U-2). This variability is perhaps not surprising because the ratio for a substance that is relatively rapidly cleared from blood could be affected by many factors including (1) the time between removal from or the last exposure to drinking water, which is not reported in studies; (2) the age of the animal and the related capacity of its mineralized tissues to take up circulating fluoride; and (3) potential interstrain and species differences in renal clearance rates.

Table U-1 Concentrations of Fluoride Measured in Tissue, Blood, Urine, or Bone

Study | Treatment^1^ | Fluoride Concentration ppm (mg/kg-d) | Internal Doses^2^
Study | Treatment^1^ | Fluoride Concentration ppm (mg/kg-d) | Brain or Other Tissue | Serum/ Plasma | Urine | Bone
Balaji et al. (2015) | Swiss albino mouse (adult, 6 ♀); drinking water for 30 days | 0 (0), 45.25 (12.27), 90.49 (24.53) | 0.083, 0.24, 0.42 | – | – | –
Balayssac et al. (2002) | Sprague Dawley rat (adult, 10 ♂); drinking water for 104 days | 0 (0), 75 (10.393), 150 (20.787) | – | 1, 5.5, 10.9 µM | – | –
| Lou/C rat (adult, 12 ♂); drinking water for 195 days | 0 (0), 150 (20.787) | | 1.1, 12.3 µM
Banji et al. (2013) | Wistar rat (adult P0 generation, 6 ♀); drinking water from GD6-PND15 | 0 (0), 61.37 (9.05) | – | P0 0.12, 0.32 (day 15) 0.14, 0.42 (day 30) | – | –
Basha et al. (2011) | Wistar rat (adult P0 generation, 8 ♀); drinking water from GD0 through lactation | 0 (0), 100 (16.025), 200 (32.051) | F1 0.318, 1.83, 2.32 CB 0.672, 2.28, 3.43 CC 0.258, 0.993, 1.93 HC 0.358, 2.12, 3.09 MO F2 0.32, 2.07, 2.61 CB 0.675, 2.89, 3.66 CC 0.256, 1.24, 2.34 HC 0.362, 2.78, 3.53 MO F3 0.319, 2.51, 2.87 CB 0.673, 3.11, 3.92 CC 0.26, 1.65, 2.73 HC 0.359, 3.03, 3.84 MO | – | – | –
Dong et al. (2015c) | Sprague Dawley rat (adult P0 generation, 30 ♂♀); drinking water from GD0-PND28 | 0.23 (0.03), 22.6 (3.27) | – | – | P0 1.7, 2.16 | P0 34.67, 211.07
Dong et al. (2015b) | Sprague Dawley rat (adult, 30 ♂♀); drinking water for 10 months | 0.23 (0.03), 22.6 (3.27) | – | – | 1.7, 2.16 | 1.52, 2.31
Ekambaram and Paul (2001) V 2001 | Wistar rat (adult, 8 ♀); drinking water for 60 days | 0 (0), 226.24 (36.26) | – | 0.22, 1.94 | – | –
Ekambaram and Paul (2002) | Wistar rat (adult, 8 ♀); drinking water for 60 days | 0.2 (0.04), 226 (40.4) | – | 0.22, 1.94 | – | –
Gao et al. (2009a) | Sprague Dawley rat (adult, 8 ♂♀); drinking water for 6 months | 0.23 (0.03), 2.26 (0.33), 22.6 (3.27) | – | – | 1.02, 2.59, 5.96 | 669.4, 1135.2, 1304.3
Gao et al. (2009b) | Sprague Dawley rat (adult, 8 ♂♀); gavage for 3 months | 0 (0), 62.68 (9.05) | – | 0.018, 7.135 | 1.462, 64.966
Gui et al. (2010) | Sprague Dawley rat (adult P0 generation, 9 ♂♀); diet for 6 months prior to mating, through lactation F1 (10 ♂♀); diet through PND30 | F1 1.77 (0.26), 29.81 (4.3) | F1 0.36, 0.74 | – | F1 0.98, 8.52 | F1 1124, 1873
Han et al. (2014) | Kunming mouse (adult, 15 ♂); drinking water for 6 months | 0 (0), 11 (2.82) 22 (5.63), 45 (11.52) | 23.5, 34.2, 38.8, 39.6 HC | – | – | –
Jiang et al. (2014b) | Sprague Dawley rat (adult, 8 ♂); drinking water for 3 months | 0 (0), 54.3 (7.52) | 0.25, 1.19 cortex 0.24, 1.14 HC | 0.09, 0.4 | – | –
Li et al. (2015) | Wistar rat (juvenile-adult, 10 ♂); drinking water for 3 months | 0 (0), 22.6 (3.34) | – | – | 6.67, 22.5 | 0.0646, 0.189
Mullenix et al. (1995) | Sprague Dawley rat (adult, 20 ♀); drinking water for 6 weeks | 0 (0), 100 (21.43) | 0.406, 0.252 BG 0.358, 0.325 CB 0.479, 0.602 cortex 0.258, 0.79 HC 0.396, 0.308 HT 0.634, 0.306 MB 0.609, 1.28 MO | 0.01, 0.077 | – | –
Niu et al. (2009) | Wistar albino rat (adult P0 generation, ♀); drinking water from GD0 to PND21 F1 (8); 12 weeks after lactation | F1 0 (0), 67.87 (10.88) | – | F1 0.59, 2.78 | – | –
Reddy and Karnati (2015) | Wistar rat (adult, 6 ♂); intraperitoneal injection for 14 days | 0, 9.05 mg/kg bw (single injection) | 0.43, 0.77 gastrocnemius muscle tissue | – | – | –
Rumiantsev et al. (1988) | Rat (adult); gavage for 30 days | 0 (0), 33.32 (5) | – | – | 14, 744 µg/24 hr urine | 2.3, 10.6 mg% thigh bone
Whitford et al. (2009) | Sprague Dawley rat (adult, 8 ♀); drinking water for 8 months | 0 (0), 33.2 (3) 85.6 (6), 155.2 (12) | 0.082, 3.9, 6.42, 18.1 µmol/kg ww | 0.32, 15.27, 25.72, 97.56 µmol/L | – | 150, 5408, 9497, 14,847 ash femur distal epiphysis

CB = cerebellum; CC = cerebral cortex; HC = hippocampus; MO = medulla oblongata; BG = basal ganglia; MB = mid-brain; HT = hypothalamus.

^1^ For two studies (Niu et al. 2009 and Rumiantsev et al. 1988), number of animals and/or sex of animals not available.

^2^ Unless otherwise noted, units for brain or other tissue and bone are provided as µg/g (units in study may have been µg/g, mg/kg, or ppm), and units for serum/plasma and urine are provided as mg/L (units in study may have been µg/mL or ppm).

Table U-2 Comparison of Drinking Water Concentration and Levels of Fluoride in Serum or Plasma

Study | Treatment | Fluoride Concentration ppm (mg/kg-d) | Internal Doses (Serum or Plasma) | Risk of Bias | Reporting Quality of LOD, Analytical Methods, and Timing of Sample Collection
Balayssac et al. (2002) | Sprague Dawley rat (adult, 10 ♂); drinking water for 104 days | 0 (0), 75 (10.393), 150 (20.787) | 1, 5.5, 10.9 µM (equivalent to 0.019, 0.1045, 0.2071 mg/L) | ++ | [underlined: LOD]: The method was linear from 0.01 to 100 mg/L fluoride with all values within this range.
| | | | ++ | [underlined: Analytical method]: Samples were collected after slight anesthesia. A combined fluoride-selective electrode ISEC 301F linked to a Meterlab PHM250® ion analyzer was used to measure plasma F concentrations.
| | | | − | [underlined: Timing]: Plasma F levels were measured at the end of the experiment, but when the experiment ended was not clear, as at least one outcome appears to have been measured 8 days after exposure ended (based on Figure 1).
| Lou/C rat (adult, 12 ♂); drinking water for 195 days | 0 (0), 150 (20.787) | 1.1, 12.3 µM (equivalent to 0.0209, 0.2337 mg/L) | ++ | [underlined: LOD]: The method was linear from 0.01 to 100 mg/L fluoride with all values within this range.
| | | | ++ | [underlined: Analytical method]: Samples were collected after slight anesthesia. A combined fluoride-selective electrode ISEC 301F linked to a Meterlab PHM250® ion analyzer was used to measure plasma F concentration.
| | | | + | [underlined: Timing]: Plasma F levels were measured at the end of the experiment, which appears to be at the end of treatment based on the time that the outcome was measured throughout treatment.
Banji et al. (2013) | Wistar rat (adult P0 generation, 6 ♀); drinking water from GD6–PND15 | 0 (0), 61.37 (9.05) | P0 0.12, 0.32 (day 15) mg/L 0.14, 0.42 (day 30) mg/L | − | [underlined: LOD]: No LOD was provided.
| | | | + | [underlined: Analytical method]: Fluoride levels were determined using a potentiometer with an ion selective electrode. No other specifics were provided.
| | | | + | [underlined: Timing]: Serum fluoride levels were determined by collecting 0.5 mL blood from the tail vein of the dam on GD20 (corresponding to 15th day of treatment) and PND11 (corresponding with 30th day of treatment), but was not measured at termination of treatment (PND15) or in the pups at the end of treatment.
Ekambaram and Paul (2001) | Wistar rat (adult, 8 ♀); drinking water for 60 days | 0 (0), 226.24 (36.26) | 0.22, 1.94 mg/L | − | [underlined: LOD]: No LOD was provided.
| | | | ++ | [underlined: Analytical method]: Serum fluoride was determined by the method using a fluoride ion specific electrode and a Fisher “accumet” model 425 pH/mV digital meter. One mL of serum was mixed with 10 mL of total ionic strength adjusting buffer in a small plastic beaker. The solution was mixed thoroughly by using a magnetic stirrer. Then the electrode was immersed in the sample solution. After the reading stabilized, the millivolt reading was recorded and expressed in mg/L.
| | | | − | [underlined: Timing]: When the blood was collected for F analysis was not stated. Blood was stated to be collected only at sacrifice for acetylcholinesterase measurement, but how long it was between treatment and sacrifice was not reported.
Ekambaram and Paul (2002) | Wistar rat (adult, 8 ♀); drinking water for 60 days | 0.2 (0.04), 226 (40.4) | 0.22, 1.94 mg/L | − | [underlined: LOD]: No LOD was provided.
| | | | ++ | [underlined: Analytical method]: Serum fluoride was determined by the method using a fluoride ion specific electrode and a Fisher “accumet” model 425 pH/mV digital meter. One mL of serum was mixed with 10 mL of total ionic strength adjusting buffer in a small plastic beaker. The solution was mixed thoroughly by using a magnetic stirrer. Then the electrode was immersed in the sample solution. After the reading stabilized, the millivolt reading was recorded and expressed in mg/L.
| | | | − | [underlined: Timing]: Blood was stated to be collected at sacrifice, but how long after treatment the animals were sacrificed was not noted.
Gao et al. (2009a) | Sprague Dawley rat (adult, 8 ♂♀); gavage for 3 months | 0 (0), 62.68 (9.05) | 0.018, 7.135 µg/mL (i.e., mg/L) | + | [underlined: LOD]: No LOD was provided in the publication, but the study cites another publication for the methods used, which reported an LOD of 0.012 µg/mL (number from “Determination for fluoride in serum-ion selective electrode method (WS / T 212-2001)”)
| | | | + | [underlined: Analytical method]: Rats were decapitated, and blood samples were taken and stored in a polyethylene tube with plug. Blood samples were centrifuged immediately to extract blood serum samples, which were stored in a refrigerator at −35 °C. All serum fluoride concentrations were determined using method “Determination for fluoride in serum-ion selective electrode method (WS / T 212-2001)” for two weeks to complete the measurement.
| | | | − | [underlined: Timing]: Blood was stated to be collected at sacrifice, but how long after treatment the animals were sacrificed was not noted. Authors noted that animals were sacrificed after the learning tests were complete, but did not indicate how many days after treatment this was.
Mullenix et al. (1995) | Sprague Dawley rat (adult, 20 ♀); drinking water for 6 weeks | 0 (0), 100 (21.43) | 0.01, 0.077 mg/L | − | [underlined: LOD]: No LODs were provided.
| | | | + | [underlined: Analytical method]: All plasma fluoride concentrations were determined using an ion-specific electrode, following hexamethyldisiloxane diffusion method.
| | | | − | [underlined: Timing]: For the adult studies, when the blood samples were obtained was not reported.
Mullenix et al. (1995) | Sprague Dawley rat (weanling, 6–19 ♂♀); drinking water for 6 or 20 weeks | 0, 75, 100, 125, 175 | | − | [underlined: LOD]: No LODs were provided.
| | | | + | [underlined: Analytical method]: All plasma fluoride concentrations were determined using an ion-specific electrode, following hexamethyldisiloxane diffusion method.
| | | | – | [underlined: Timing]: Fluoride levels were measured 3 weeks after exposure.
Niu et al. (2009) | Wistar albino rat (adult P0 generation, ♀); drinking water from GD0 to PND21 F1 (8); 12 weeks after lactation | F1 0 (0), 67.87 (10.88) | F1 0.59, 2.78 mg/L **units unclear, listed as mg/L, µg/dL, and µg/dL in article | − | [underlined: LOD]: No LODs were provided.
| | | | − | [underlined: Analytical method]: Analytical methods were not reported.
| | | | − | [underlined: Timing]: How or when blood samples were collected for analysis was not reported. Animals were sacrificed after the learning tests were complete, but authors gave no indication of how many days after treatment this was.
Whitford et al. (2009) | Sprague Dawley rat (adult, 8 ♀); drinking water for 8 months | 0 (0), 33.2 (3), 85.6 (6), 155.2 (12) | 0.32, 15.27, 25.72, 97.56 µmol/L (equivalent to 0.006, 0.290, 0.489, 1.854 mg/L) | − | [underlined: LOD]: No LODs were provided.
| | | | ++ | [underlined: Analytical method]: Plasma was analyzed for fluoride using an ion-specific electrode (Orion Research, Model 9409) and a reference electrode (Orion, Model 90-01) coupled to a potentiometer (Orion Research, Model 720A) after overnight hexamethyldisiloxane (HMDS)-facilitated diffusion. The next day the alkaline trap, 50 μL of 0.05 N NaOH, was allowed to air dry. The NaOH crystals were dissolved by adding 20 μL of 0.20 N acetic acid to form an acetate buffer system (pH 5.2). This solution was transferred to the sensing surface of the inverted reference electrode and the fluoride electrode was lowered until it contacted the solution. The mV potential was recorded after a stable reading had been obtained, which occurred within 2–4 min. Three fluoride standards, each in triplicate, calculated to bracket the expected amounts of fluoride in the different tissues, were diffused along with the samples. The r2 values for every standard curve exceeded 0.97. Non-diffused standards also were analyzed. These standards were prepared with the same reagents used to prepare the diffused standards and to have the same concentrations as the diffused standards. Comparison of the mV potentials of the diffused and non-diffused standards confirmed fluoride in the diffused standards had been completely trapped and analyzed (range of agreement 96–102%).
| | | | − | [underlined: Timing]: Authors noted that blood was collected 4 days after completion of the behavioral studies, but when this was in terms of completion of the fluoride treatment was not clear (presumably 4 days or more after completion of treatment). In addition, authors noted that samples were placed in the refrigerator until analysis, but did not note the length of time until the samples were analyzed.