# Appendix T Fluoride Administered and Converted Doses (Range across Studies for a Given ppm Level)

Table T-1 Summary of Fluoride Administered and Converted Doses (Across Studies)

Fluoride Concentrations^1^ ppm | Fluoride Concentrations^1^ mg/kg-d | References
Oral Drinking Water
0.20 | 0.03–0.04 | Ekambaram and Paul (2001; 2002)
0.23 | 0.03 | Gao et al. (2009a); Liu et al. (2010); Liu et al. (2009)
0.30 | 0.07 | Kivrak (2012)
0.34 | 0.05 | Jiang et al. (2014a)
0.45 | 0.12 | Zhang et al. (2001); Zhang et al. (1999)
0.50 | 0.07 | Dong et al. (2015a); Dong et al. (2015b); Dong et al. (2015c); Gao et al. (2008a); Jetti et al. (2016); Liu et al. (2011); Raghu et al. (2013)
0.54 | 0.08 | Bataineh and Nusier (2006)
0.60 | 0.01–0.13 | Wang et al. (2004); Wu et al. (2008)
0.70 | 0.05–0.10 | Chioca et al. (2008); Pereira et al. (2011)
0.90 | 0.23 | Liu et al. (2014)
1.0 | 0.14–0.21 | Basha et al. (2011); Gao et al. (2008b); Wu et al. (2008)
1.1 | 0.18 | Zhang et al. (2009)
1.4 | 0.35 | Xu et al. (2001)
2.3 | 0.27–0.59 | Bartos et al. (2015); Gao et al. (2009a); Gao et al. (2008a); Gao et al. (2008b); Liu et al. (2014); Liu et al. (2011); Liu et al. (2010); Liu et al. (2009); Zhang et al. (2009); Zhang et al. (2001); Zhang et al. (1999); Zhu et al. (2012)
2.7 | 0.7 | Xu et al. (2001)
4.5 | 0.54–1.19 | Bartos et al. (2015); Liu et al. (2014); Zhang et al. (2009); Zhang et al. (2001); Zhang et al. (1999); Zhu et al. (2012)
5.0 | 1.1 | Wu et al. (2008)
5.4 | 1.4 | Xu et al. (2001)
9.1 | 1.34 | Zhu et al. (2012)
10.0 | 2.6 | Sun et al. (2008)
11.0 | 2.8 | Han et al. (2014)
11.3 | 1.6 | Jiang et al. (2014a)
11.8 | 1.8 | Jain et al. (2015)
13.6 | 2.2 | Liu (1989)
18.5 | 5.0 | Bǎran-Poesina et al. (2013)
22.0 | 5.6 | Han et al. (2014)
22.6 | 2.3–5.8 | Chen and Geng (2011); Chioca et al. (2008); Dong et al. (2015b); Dong et al. (2015c); El-lethey et al. (2011); El-lethey et al. (2010); Gao et al. (2009a); Gao et al. (2008a); Gao et al. (2008b); Jiang et al. (2014a); Li et al. (2015); Liu et al. (2011); Liu et al. (2010); Liu et al. (2009) Ma et al. (2015)
25.0 | 5.3 | Wu et al. (2008)
27.2 | 4.4 | Liu (1989)
33.2 | 3 | Whitford et al. (2009)
37.1 | 10 | Bǎran-Poesina et al. (2013)
40.0 | 9.6 | Kivrak (2012)
45.0 | 11.5 | Han et al. (2014)
45.2–45.3 | 4.9–12.3 | Balaji et al. (2015); Chen and Geng (2011); Chioca et al. (2008); El-lethey et al. (2011); El-lethey and Kamel (2011); El-lethey et al. (2010); El-lethey and Shaheed (2011); Hong et al. (2005); Jiang et al. (2014a); Wang et al. (2006); Wang et al. (2004); Wu et al. (2006) Bataineh and Nusier (2006); Ma et al. (2015); Pereira et al. (2011)
50.0 | 13.1 | Sun et al. (2008)
54.3 | 7.5–14.7 | Bhatnagar et al. (2002); Jiang et al. (2014b)
61.4 | 9.1 | Banji et al. (2013)
67.9 | 9.8–18.4 | Chen and Geng (2011); Niu et al. (2014); Niu et al. (2009); Niu et al. (2008); Shen et al. (2004)
75.0 | 10.4 | Balayssac et al. (2002)
85.6 | 6 | Whitford et al. (2009)
90.5 | 13.8–24.5 | Balaji et al. (2015); Wang et al. (2006)
100 | 14.8–26.3 | Basha et al. (2011); Jetti et al. (2016); Mullenix et al. (1995); Raghu et al. (2013); Sun et al. (2008) (6-wk exposure)
125 | 19 | Mullenix et al. (1995) (16-wk exposure)
135.7 | 18.8 | Bataineh and Nusier (2006)
150 | 20.8 | Balayssac et al. (2002)
155.2 | 12 | Whitford et al. (2009)
200 | 32 | Basha et al. (2011)
226 | 36.3–110.7 | Ekambaram and Paul (2001; 2002); Ekambaram and Paul (2003)
271.5 | 40.0 | Basha and Sujitha (2012)
Oral Diet
1.8 | 0.3 | Gui et al. (2010)
4.2 | 0.6 | Elliott (1967)
29.8 | 4.3 | Gui et al. (2010)
42.4 | 6.1 | Elliott (1967)
Gavage
0.45 | 0.07 | Wei et al. (2014)
7.1 | 1.1 | Bera et al. (2007); Flace et al. (2010)
14.1 | 2.3 | Bera et al. (2007); Flace et al. (2010)
14.8 | 2.3 | Sarkozi et al. (2015)
22.6 | 3.4 | Wei et al. (2014)
31.3 | 4.5 | Gopal et al. (2006)
33.3 | 5.0 | Rumiantsev et al. (1988)
45.3 | 6.7 | Zhang et al. (2013)
56.5 | 9.1 | Paul et al. (1998)
62.6 | 9.1 | Gopal et al. (2006)
62.7 | 9.1 | Gao et al. (2009b)
112.9 | 18.1 | Paul et al. (1998)
Subcutaneous or Intraperitoneal Injection
– | 0.06 (9 prenatal injections) | Mullenix et al. (1995)
– | 9.1 (single injection) | Reddy and Karnati (2015)

In general, the administered chemical in studies is sodium fluoride (NaF), and not all studies provide F equivalents. Dose levels are presented here as average daily doses of fluoride (mg/kg-d) and equivalent water concentrations of fluoride (ppm). As needed, dose conversions were made using US EPA (1988; 1994) default food or water consumption rates and body weights (using subchronic age and experiment duration) for the species/strain and sex of the animal of interest. Dose levels in mg/kg-d can vary for a given ppm across different studies if the studies use different species/strains and sex of animals that are assumed to have different water consumption rates.