# Appendix S Fluoride Administered and Converted Doses (Individual Studies)

Table S-1 Summary of Fluoride Administered and Converted Doses (Individual Studies)

Study | Fluoride Concentration^1^ ppm | Fluoride Concentration^1^ mg/kg-d
Oral Drinking Water
Balaji et al. (2015) | 0, 45.3, 90.5 | 0, 12.3, 24.5
Balayssac et al. (2002) | 0, 150 (Lou/C rat) 0, 75, 150 (SD rat) | 0, 20.8 (Lou/C rat) 0, 10.4, 20.8 (SD rat)
Banji et al. (2013) | 0, 61.4 (F1) | 0, 9.1 (F1)
Bǎran-Poesina et al. (2013) | 0, 18.5, 37.1 (P0, F1, F2) | 0, 5, 10 (P0, F1, F2)
Bartos et al. (2015) | 0, 2.3, 4.5 (F1) | 0, 0.27, 0.54 (F1)
Basha and Sujitha (2012) | 0, 271.5 | 0, 40
Basha et al. (2011) | 1, 100, 200 (F1, F2, F3) | 0.16, 16.03, 32.1 (F1, F2, F3)
Bataineh and Nusier (2006) | 0.54, 45.3, 135.7 | 0.08, 6.3, 18.8
Bhatnagar et al. (2002) | 0, 54.3 | 0, 14.7
Chen and Geng (2011) | 0, 22.6, 45.2, 67.9 | 0, 3.3, 6.7, 10
Chioca et al. (2008) | 0.7, 22.6, 45.2 | 0.045, 2.33, 4.87
Dong et al. (2015a); Dong et al. (2015b); Dong et al. (2015c) | 0.5, 22.6 (F1) | 0.07, 3.3 (F1)
Ekambaram and Paul (2003) | 0.2, 226 | 0.03, 36.3
Ekambaram and Paul (2002) | 0.2, 226 | 0.04, 40.4
Ekambaram and Paul (2003) | 0, 226 | 0, 110.7
El-lethey et al. (2010) | 0, 22.6, 45.3 (F1) | 0, 2.3, 4.9 (F1)
El-lethey et al. (2011) | 0, 22.6, 45.3 (F1) | 0, 3.1, 6.3 (F1)
El-lethey and Shaheed (2011) | 0, 45.3 | 0, 6.7
El-lethey and Kamel (2011) | 0, 45.3 | 0, 6.7
Gao et al. (2008a) | 1, 2.3, 22.6 | 0.14, 0.33, 3.3
Gao et al. (2008b) | 0.5, 2.3, 22.6 | 0.07, 0.33, 3.3
Gao et al. (2009a) | 0.23, 2.7, 22.6 | 0.03, 0.33, 3.3
Han et al. (2014) | 0, 11, 22, 45 | 0, 2.8, 5.6, 11.5
Hong et al. (2005) | 0, 45.3 (F1) | 0, 6.9 (F1)
Jain et al. (2015) | 0, 11.8 | 0, 1.8
Jetti et al. (2016) | 0.5, 100 | 0.07, 14.8
Jiang et al. (2014a) | 0.3, 11.3, 22.6, 45.3 (F1) | 0.05, 1.6, 3.3, 6.5 (F1)
Jiang et al. (2014b) | 0, 54.3 | 0, 7.5
Kivrak (2012) | 0.3, 40 | 0.07, 9.6
Li et al. (2015) | 0, 22.6 | 0, 3.3
Liu (1989) | 0, 13.6, 27.2 (F1) | 0, 2.2, 4.4 (F1)
Liu et al. (2009) | 0.23, 2.3, 22.6 | 0.03, 0.3, 3.3
Liu et al. (2010) | 0.23, 2.3, 22.6 | 0.03, 0.3, 3.3
Liu et al. (2011) | 0.5, 2.3, 22.6 | 0.07, 0.3, 3.3
Liu et al. (2014) | 0, 0.9, 2.3, 4.5 | 0, 0.23, 0.58, 1.2
Ma et al. (2015) | 0, 22.6, 45.2 | 0, 5.79, 11.6
Mullenix et al. (1995) (6-wk exposure) | 0, 100 | 0, 21.46
Mullenix et al. (1995) (16-wk exposure) | 0, 125 | 0, 19
Niu et al. (2008) | 0, 67.9 | 0, 10.4
Niu et al. (2009) | 0, 67.9 (F1) | 0, 10.9 (F1)
Niu et al. (2014) | 0, 67.9 (F1) | 0, 18.4 (F1)
Pereira et al. (2011) | 0.7, 45.2 | 0.1, 6.7
Raghu et al. (2013) | 0.5, 100 | 0.07, 14.8
Shen et al. (2004) | 0, 67.9 | 0, 9.8
Sun et al. (2008) | 0, 10, 50, 100 | 0, 2.6, 13.1, 26.3
Wang et al. (2004) | 0.6, 45.3 (F1) | 0.01, 6.9 (F1)
Wang et al. (2006) | 0, 45.3, 90.5 | 0, 6.9, 13.8
Wei et al. (2014)
Whitford et al. (2009) | 0, 33.2, 85.6, 155.2 | 0, 3, 6, 12
Wu et al. (2006) | 0, 45.3 | 0, 5.8
Wu et al. (2008) | 0.6, 25 (F1 postnatal) 0.6, 1, 5, 25 (F1 prenatal and postnatal) | 0.1, 5.3 (F1 postnatal) 0.1, 0.2, 1.1, 5.3 (F1 prenatal and postnatal)
Xu et al. (2001) | 0, 1.4, 2.7, 5.4 | 0, 0.4, 0.7, 1.4
Zhang et al. (1999) | 0, 0.5, 2.3, 4.5 | 0, 0.1, 0.6, 1.2
Zhang et al. (2001) | 0, 0.5, 2.3, 4.5 | 0, 0.1, 0.6, 1.2
Zhang et al. (2009) | 0, 1.1, 2.3, 4.5 (F1) | 0, 0.18, 0.36, 0.71 (F1)
Zhu et al. (2012) | 0, 2.3, 4.5, 9.05 | 0, 0.34, 0.68, 1.4
Oral diet
Elliott (1967) | 0, 4.2, 42.4 | 0, 0.61, 6.2
Gui et al. (2010) | 1.8, 29.8 (F1) | 0.26, 4.3 (F1)
Gavage
Bera et al. (2007) | 0, 7.1, 14.1 (F1) | 0, 1.1, 2.3 (F1)
Flace et al. (2010) | 0, 7.1, 14.1 (F1) | 0, 1.1, 2.3 (F1)
Gao et al. (2009a) | 0, 62.7 | 0, 9.05
Gopal et al. (2006) | 0, 31.3, 62.6 | 0, 4.52, 9.05
Paul et al. (1998) | 0, 56.5, 112.9 | 0, 9.05, 18.1
Rumiantsev et al. (1988) | 0, 33.3 | 0, 5
Sarkozi et al. (2015) | 0, 14.8 | 0, 2.3
Wei et al. (2014) | 0.5, 22.6 (F1) | 0.07, 3.44 (F1)
Zhang et al. (2013) | 0, 45.3 | 0, 6.7
Subcutaneous or Intraperitoneal Injection
Mullenix et al. (1995) | – | 0, 0.06 mg/kg (P0) (9 prenatal injections)
Reddy and Karnati (2015) | – | 0, 9.05 mg/kg bw (single injection)

^1^ In general, the administered chemical in studies is sodium fluoride (NaF), and not all studies provide F equivalents. Dose levels are presented here as average daily doses of fluoride (mg/kg-d) and equivalent water concentrations of fluoride (ppm). As needed, dose conversions were made using US EPA (1988; 1994) default food or water consumption rates and body weights (using subchronic age and experiment duration) for the species/strain and sex of the animal of interest. Dose levels in mg/kg-d can vary for a given ppm across different studies if the studies use different species/strains and sex of animals that are assumed to have different water consumption rates.