# Appendix R Other

Figure R-1

Other

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/other/) (B) Risk of bias assessments for individual studies (https://hawcproject.org/summary/visual/69/)(*study excluded from primary analysis due to concerns for risk of bias).