# Appendix Q Territorial Aggression

Figure Q-1

Territorial Aggression

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-social-territorial-aggression/)(B) Risk of bias across studies. (https://hawcproject.org/summary/visual/76/) (C) Risk of bias assessments for individual studies (https://hawcproject.org/summary/visual/75/)(*study excluded from primary analysis due to concerns for risk of bias).