# Appendix O Grooming, Defecation, Urination

Figure O-1

Grooming, Defecation, Urination

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-grooming-urination-defecation/) Note: The following endpoint from Wu et al. (2008) was described as not affected (data not shown): defecation and urination in open field test. (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/28/) (C) Risk of bias assessments for (https://hawcproject.org/summary/visual/27/) individual studies (https://hawcproject.org/summary/visual/27/)(*study excluded from primary analysis due to concerns for risk of bias).