# Appendix M Motor and Sensory Function: Reflex and Motor Sensory Development

Figure M-1

Motor and Sensory Function: Reflex and Motor Sensory Development

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-motor-and-sensory-function-reflex/) Note: The following endpoints from Wu et al. (2008) were described as not affected (data not shown): auditory startle, cliff avoidance, negative taxis, pivoting task, surface righting. (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/67/) (C) Risk of bias assessments for individual studies (https://hawcproject.org/summary/visual/66/)(*study excluded from primary analysis due to concerns for risk of bias).