# Appendix L Motor and Sensory Function: Movement Coordination

Figure L-1

Motor and Sensory Function: Movement Coordination

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-motor-and-sensory-function-movement-coordina/) Note: For Bhatnagar et al. (2002), data presented in paper only for control and high dose groups (0-, 3.68-, 7.37-, and 14.72-ppm dose groups were tested) and data for (catalepsy, latency time) are not included in figure because control values were not presented in paper (findings described as “a significant high value was observed in treated animals (7.0 +/- 3.3).” The following endpoints from Wu et al. (2008) were described as not affected (data not shown): swim test, slanted surface, forelimb suspension. (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/61/) (C) Risk of bias assessments for (https://hawcproject.org/summary/visual/60/) individual studies (https://hawcproject.org/summary/visual/60/)(*study excluded from primary analysis due to concerns for risk of bias).