# Appendix K Motor and Sensory Function: Locomotor Activity

Figure K-1

Motor and Sensory Function: Locomotor Activity

(A) Descriptive features and results of studies expressed as percent change from control response. Click the following link to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-motor-and-sensory-function-locomotor-activit/) Note: Findings for Bera et al. (2007) are not shown because a single conclusion on “locomotor activity” was reported (no significant effects, data not shown). (B) Risk of bias (https://hawcproject.org/summary/visual/58/) across studies. (https://hawcproject.org/summary/visual/58/)(C) Risk of bias assessments for individual studies (https://hawcproject.org/summary/visual/57/)(*study excluded from primary analysis due to concerns for risk of bias).