# Appendix J Learning and Memory: Active Avoidance

Figure J-1

Learning and Memory: Active Avoidance

(A) Descriptive features and results of studies expressed as percent change from control response. Click to see interactive graphic sorted by study. (https://hawcproject.org/summary/data-pivot/assessment/126/study-learning-and-memory-active-avoidance/)Note: Data from Wang et al. (2004) for active avoidance (step-down test, number of shocks, session 2, day 30) could not be plotted as percent change from control because the response and SD were 0 in the control group. A significant increase in the number of shocks was observed in the 45-ppm treatment group. (B) Risk of bias across studies. (https://hawcproject.org/summary/visual/43/) (C) Risk of bias assessments for individual (https://hawcproject.org/summary/visual/42/) studies (https://hawcproject.org/summary/visual/42/)(*study excluded from primary analysis due to concerns for risk of bias).